# Results

## Rats

### Survival

All rats in all exposure groups, except for the 720 ppm (60 mg (+/−)-usnic acid/kg body weight/day [mg/kg/day]) exposed group, survived to terminal sacrifice (Table 6). Both female and male rats in the 720 ppm exposure groups exhibited significant weight loss and morbidity. By the sixth week of exposure, all 10 of the males and 9 of the females had been removed from the study due to death or morbidity (Figure 2). However, one female rat survived to the end of the study and only exhibited moderate weight loss.

Table 6 Survival, Disposition, and Body Weights of Rats in the Three-month Feed Study of Usnea Lichens

Parameter^a^ | 0 ppm | 30 ppm (2.5)^b^ | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 720 ppm (60)
Male
Rats Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 0
Moribund | 0 | 0 | 0 | 0 | 0 | 10
Rats Surviving to Study Termination | 10 | 10 | 10 | 10 | 10 | 0
Probability of Survival to End of Study | 100% | 100% | 100% | 100% | 100% | 0%
Mean Survival (days)^c^ | 94 | 94 | 94 | 94 | 94 | 32.3
Initial Body Weight (g)^d^ | 196.4 ± 3.8 | 195.9 ± 3.9 | 194.6 ± 3.6 | 201.6 ± 7.1 | 195.2 ± 5.0 | 195.5 ± 4.9
Final Body Weight (g)^d^ | 352.6 ± 5.9** | 351.3 ± 5.9 | 353.9 ± 4.7 | 350.0 ± 5.9 | 331.9 ± 7.3* | 127.8 ± 2.3***^e^
Change in Body Weight (g) | 156.2 | 155.4 | 159.3 | 148.4 | 136.7 | −67.7^e^
Final Weight as % of Controls | –^f^ | 99.6 | 100.4 | 99.3 | 94.1 | 46.0^e^
Observed Dose (mg/kg/day)^g^ | – | 2.14 ± 0.04 | 4.21 ± 0.10 | 8.70 ± 0.21 | 28.3 ± 0.61 | 69.9 ± 4.52^h^
Female
Rats Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 1
Moribund | 0 | 0 | 0 | 0 | 0 | 8
Rats Surviving to Study Termination | 10 | 10 | 10 | 10 | 10 | 1
Probability of Survival to End of Study | 100% | 100% | 100% | 100% | 100% | 10%
Mean Survival (days) | 94 | 94 | 94 | 94 | 94 | 28.1
Initial Body Weight (g) | 140.0 ± 2.4 | 141.5 ± 3.3 | 145.2 ± 2.5 | 141.1 ± 3.2 | 141.5 ± 2.7 | 139.6 ± 2.1
Final Body Weight (g) | 202.1 ± 3.8*** | 205.9 ± 5.8 | 210.6 ± 4.1 | 198.8 ± 4.2 | 186.1 ± 2.6*** | 105.0 ± 13.3***^i^
Change in Body Weight (g) | 62.1 | 64.4 | 65.4 | 57.7 | 44.6 | −34.6^i^
Final Weight as % of Controls | – | 101.9 | 104.2 | 98.4 | 92.1 | 58.9^i^
Observed Dose (mg/kg/day) | – | 2.59 ± 0.05 | 5.38 ± 0.08 | 11.14 ± 0.21 | 34.2 ± 0.63 | 83.5 ± 5.36^h^

^a^ Complete details of the dosing schedule are given in the methods section.

^b^ Denotes target dose as mg (+/−)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Animals were assigned to the study for 94 days but were exposed to feed for 90 days.

^d^ Body weight (g) as mean ± standard error. Asterisks denote significant dose trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^e^ Weights of surviving animals at week 5 of study (N = 9), statistical analysis and percentage compared to week 5 control.

^f^ Not applicable.

^g^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving rats in each exposure group. Observed feed consumption values do not correct for spillage. Data presented as mean ± standard error for the 13 weekly values.

^h^ Data for 6 weeks only.

^i^ Weights of surviving animals at week 5 of study (N = 6), statistical analysis and percentage compared to week 5 control.

Figure 2

Survival Curves for Male and Female Rats Exposed to Usnea Lichens in Feed for Three Months

### Body and Organ Weight Analysis

Body weight curves are shown in Figure 3. For both female and male F344/N Nctr rats, severe weight loss was observed at the highest exposure (720 ppm). There were significant exposure trends with lower mean body weight at higher levels of exposure. There were statistically significant differences in mean body weights between the 360 and 720 ppm groups and the control group for both females and males. Final mean body weights in the 360 ppm groups were 94.1% and 92.1% of the control group values for males and females, respectively (Table 6, Appendix D). Exposure to the lichens did not significantly alter feed consumption in any group other than the 720 ppm group. In the latter, feed consumption was significantly reduced during weeks 1 and 4 for the males and during week 1 for the females (Appendix F). Observed mean body weights and feed consumption values were similar to historical control values used to set the dose concentrations in the feed so that the observed mean doses in mg /kg/day during the study were similar to the target dose values (Table F-5, Appendix F).

Figure 3

Growth Curves for Male and Female Rats Exposed to Usnea Lichens in Feed for Three Months

Plotted as mean body weights of each exposure group, but without surviving females in 720 ppm group.

Absolute and relative organ weights are reported in Appendix E. For both sexes, exposure to (+/−)-usnic acid in Usnea lichens had a significant effect on liver weight. Mean relative liver weights were higher in the 360 ppm exposure group than for controls for females and males and in the 120 ppm exposure group for females. There was also a significant decrease in absolute right kidney weight and significant increases in relative thymus, left testis, and right testis weights between the 360 ppm exposure group and the control group for males.

### Pathology and Statistical Analyses

The only gross observations in rats that may have had an exposure relationship were thymic and seminal vesicular atrophy, which were observed in animals in the 720 ppm exposure group. The remainder of the gross observations were considered common background changes. No neoplasms were observed in any animal.

Of the observed histopathological changes, only lesions in the liver were evident at lower exposures. Hepatocellular degeneration (Figure 4, Figure 5) was observed in both male (Table 7) and female rats (Table 8) exposed to (+/−)-usnic acid in Usnea lichens. Incidence and severity of these lesions were increased in the 120, 360, and 720 ppm exposure groups in males, and incidence was increased in the 720 ppm exposure group in females. One male rat in the 60 ppm exposure group also exhibited hepatocellular degeneration and inflammation with an average severity grade of 2, but this observation was not statistically significant for the exposed group. The affected animals displayed one or more of the following changes, which are associated with hepatocellular toxicity: cell swelling as well as cell contraction, cytoplasmic vacuolization or clearing, clumping (increased densities) of organelles, and in many animals an increased cytoplasmic eosinophilia. These lesions were primarily noted in the centrilobular zone with midzonal involvement in many of the same animals. Nuclear chromatin clumping with early karyorrhexis was occasionally observed along with single necrotic cells characterized by their dark appearance and being dislodged from their normal position. The vacuolar degeneration that was observed may represent one or more of the following: (1) water accumulation with distortion of endoplasmic reticulum following cellular membrane damage, (2) markedly dilated mitochondria due to a primary injury to mitochondria, and (3) lipidosis, a result of an overload of metabolic pathways. These changes represent patterns of cell degeneration with differences depending on the exposure and the state of metabolism in the cell at the time of injury. The lesions described are part of a cascade of factors leading to irreversible degeneration and eventually necrosis. Chronic inflammation was frequently present with these degenerative changes. Liver tissue was examined microscopically in groups with progressively lower levels of exposure until a no-observed-adverse-effect level (NOAEL) was reached at 60 ppm for males and 360 ppm for females.

Figure 4

Section of the Liver from 0 ppm F344/N Nctr Rats from the Three-month Feed Study of Usnea Lichens (H&E)

H&E = hematoxylin and eosin stain.

Figure 5

Section of the Liver from 720 ppm F344/N Nctr Rats from the Three-month Feed Study of Usnea Lichens (H&E)

H&E = hematoxylin and eosin stain.

Table 7 Statistical Analysis of Select Nonneoplastic Lesions in Male Rats in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 30 ppm (2.5)^b^ | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 720 ppm (60)
Liver
Hepatocellular Degeneration
Overall rate^c^ | 1/10 (10.0%) | 0/10 (0.0%) | 1/10 (10.0%) | 6/10 (60.0%) | 10/10 (100.0%) | 10/10 (100.0%)
Terminal rate^d^ | 1/10 (10.0%) | 0/10 (0.0%) | 1/10 (10.0%) | 6/10 (60.0%) | 10/10 (100.0%) | –^e^
CAFÉ p value^f^ | p ≤ 0.001 | p = 0.500N | p = 0.763 | p = 0.029 | p ≤ 0.001 | p ≤ 0.001
Average severity^g^ | 1.0 | – | 2.0 | 1.2 | 1.8 | 3.7
Adrenal Cortex
Vacuolization Cytoplasmic
Overall rate | 4/10 (40.0%) | – | – | – | 2/10 (20.0%) | 10/10 (100.0%)
Terminal rate | 4/10 (40.0%) | – | – | – | 2/10 (20.0%) | 10/10 (100.0%)
CAFÉ p value | p = 0.007 | – | – | – | p = 0.314N | p = 0.005
Average severity | 1.5 | – | – | – | 1.5 | 4.0
Thymus
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 9/10 (90.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 3.8
Prostate
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 4.0
Seminal Vesicle
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 4.0
Testes
Seminiferous Tubule Degeneration
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%)
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 4.0
Bone Marrow
Hypocellularity
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 3.6

^a^ Complete details of the dosing schedule are given in the methods section.

^b^ Denotes target dose as mg (+/−)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^d^ Observed incidence at terminal sacrifice.

^e^ Indicates no data were collected.

^f^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N. Significant p values are bolded.

^g^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Table 8 Statistical Analysis of Select Nonneoplastic Lesions in Female Rats in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 30 ppm (2.5)^b^ | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 720 ppm (60)
Liver
Hepatocellular Degeneration
Overall rate^c^ | 0/10 (0.0%) | –^d^ | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate^e^ | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 1/1 (100.0%)
CAFÉ p value^f^ | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity^g^ | – | – | – | – | – | 3.2
Adrenal Cortex
Vacuolization Cytoplasmic
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 8/9 (88.9%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p = 0.001
Average severity | – | – | – | – | – | 3.6
Thymus
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 8/10 (80.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 3.9
Bone Marrow
Hypocellularity
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 8/9 (88.9%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 3.9

^a^ Complete details of the dosing schedule are given in the methods section.

^b^ Denotes target dose as mg (+/−)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^d^ Indicates no data were collected.

^e^ Observed incidence at terminal sacrifice.

^f^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N. Significant p values are bolded.

^g^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In addition, exposure of both male and female F344/N Nctr rats to 720 ppm (+/−)-usnic acid in Usnea lichens produced a series of lesions including thymic atrophy, cytoplasmic vacuolization of the adrenal cortex, and effects on bone marrow and the reproductive system, which are characteristic of toxic stress (Table 7, Table 8). All male and 9 of the 10 female rats were removed from the study, due to early death or morbidity, by the sixth week of dosing. The female rat that survived until the end of the study did not exhibit thymic atrophy, cytoplasmic vacuolization of the adrenal cortex, or bone marrow hypocellularity and exhibited only mild hepatocellular degeneration.

Morbidity in rats exposed to 720 ppm (+/−)-usnic acid in Usnea lichens was also associated with significant changes in clinical chemistry parameters (Appendix C). In male rats, these changes included significant increases in serum alanine aminotransferase and creatinine kinase activities and decreases in blood hemoglobin, hematocrit, and platelet count. In female rats, these included significantly increased alanine aminotransferase and alkaline phosphatase activities and decreased blood hemoglobin, hematocrit, and platelet count in females (Table C-1).

The 720 ppm exposure groups were not evaluated for reproductive toxicity due to their early removal from the study. The control, 60, 120, and 360 ppm exposure groups were evaluated (Appendix G). There were no significant differences in any andrological endpoints in any of the exposure groups relative to control values. In females, all animals were cycling normally, but there was a small statistically significant increase in estrus stage length in the 360 ppm exposure group.

## Mice

### Survival

One female mouse died prematurely in the 360 ppm (60 mg/kg/day) exposure group after 18 days on study (14 days of exposure), and one female mouse in the control group became moribund and was removed from study at 55 days on study (51 days of exposure). All other mice in all exposure groups survived until terminal sacrifice (Table 9).

Table 9 Survival, Disposition, and Body Weights of Mice in the Three-Month Feed Study of Usnea Lichens

Parameter^a^ | 0 ppm | 15 ppm (2.5)^b^ | 30 ppm (5) | 60 ppm (10) | 180 ppm (30) | 360 ppm (60)
Male
Mice Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 0
Moribund | 0 | 0 | 0 | 0 | 0 | 0
Mice Surviving to Study Termination | 10 | 10 | 10 | 10 | 10 | 10
Probability of Survival to End of Study | 100% | 100% | 100% | 100% | 100% | 100%
Mean Survival (days)^c^ | 94 | 94 | 94 | 94 | 94 | 94
Initial Body Weight (g)^d^ | 22.3 ± 0.3 | 22.6 ± 0.4 | 22.2 ± 0.3 | 22.5 ± 0.3 | 22.1 ± 0.4 | 22.8 ± 0.3
Final Body Weight (g)^d^ | 30.5 ± 0.7*** | 30.4 ± 0.5 | 30.6 ± 0.5 | 29.9 ± 0.7 | 29.3 ± 0.5 | 28.0 ± 0.4**
Change in Body Weight (g) | 8.2 | 7.8 | 8.4 | 7.4 | 7.2 | 5.2
Final Weight as % of Controls | –^e^ | 99.7 | 100.3 | 98.0 | 96.1 | 91.8
Observed Dose (mg/kg/day)^f^ | – | 3.72 ± 0.12 | 7.34 ± 0.18 | 15.01 ± 0.26 | 50.7 ± 1.41 | 104.4 ± 3.06
Female
Mice Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 1
Moribund | 1 | 0 | 0 | 0 | 0 | 0
Mice Surviving to Study Termination | 9 | 10 | 10 | 10 | 10 | 9
Probability of Survival to End of Study | 90% | 100% | 100% | 100% | 100% | 90%
Mean Survival (days) | 90.4 | 94 | 94 | 94 | 94 | 86.5
Initial Body Weight (g) | 17.4 ± 0.3 | 17.0 ± 0.3 | 16.9 ± 0.3 | 17.7 ± 0.3 | 17.7 ± 0.3 | 17.2 ± 0.2
Final Body Weight (g) | 24.9 ± 0.7*** | 24.9 ± 0.5 | 24.3 ± 0.5 | 24.8 ± 0.6 | 24.3 ± 0.4 | 21.7 ± 0.3***
Change in Body Weight (g) | 7.5 | 7.9 | 7.4 | 7.1 | 6.6 | 4.5
Final Weight as % of Controls | – | 100.0 | 97.6 | 99.6 | 97.6 | 87.1
Observed Dose (mg/kg/day) | – | 4.84 ± 0.14 | 9.91 ± 0.22 | 19.84 ± 0.35 | 57.61 ± 1.70 | 136.6 ± 4.70

^a^ Complete details of the dosing schedule is given in the methods section.

^b^ Denotes target dose as mg (+/−)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Animals were assigned to the study for 94 days but were exposed to feed for 90 days.

^d^ Body weight (g) as mean ± standard error. Asterisks denote significant exposure trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.01 (**); p ≤ 0.001 (***).

^e^ Not applicable.

^f^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving mice in each exposed group. Observed feed consumption values do not correct for spillage. Data presented as mean ± standard error for the 13 weekly values.

### Body and Organ Weight Analysis

For both male and female B6C3F1/Nctr mice, there was a small decrease in body weight in the 360 ppm exposure group compared to controls (Figure 6; Appendix D). The overall and weekly mean body weights showed significant differences in the 360 ppm exposure group compared to the control group, with decreased mean body weights observed with higher levels of exposure (Table 9). There was a significant effect of exposure level on liver weight in both males and females, and for heart, right kidney, and thymus weights in males (Appendix E). Both absolute and relative liver weights were significantly higher for the exposed groups compared to the control group in the 180 ppm and 360 ppm exposed groups in females and in the 180 and 360 ppm exposed groups in males. Absolute liver weights were approximately 21.9% and 38.8% higher in the 180 and 360 ppm groups in males, respectively, and 16.7% and 32.0% higher in females, respectively. Absolute and relative thymus weights were also significantly increased in the males at 360 ppm, with absolute weights approximately 26.9% higher than the control group. Absolute heart and right kidney weights were decreased in the 360 ppm males by 11.4% and 10.9%, respectively, and absolute lung and right kidney weights in the 360 ppm females were decreased by 22.0% and 11.2% respectively. Relative weights were not significantly changed in any exposed group for the heart, right kidney, or lung (Appendix E). The lichen did not significantly alter feed consumption in any exposed group (Appendix F). Observed mean body weights were similar, but observed feed consumption values were greater than historical control values used to set the exposure concentrations in the feed so that the observed mean doses of (+/−)-usnic acid (mg/kg/day) during the study were greater than the target dose values (Table 9; Appendix F). Because of this, exposure levels for these studies are based on the ppm concentration of (+/-)-usnic acid in feed and target mg/kg/day values are provided as an approximate comparison to human exposure levels.

Figure 6

Growth Curves for Male and Female Mice Exposed to Usnea Lichens in Feed for Three Months

Plotted as mean body weights of each exposure group.

### Pathology and Statistical Analyses

There were no exposure-related gross observations or neoplasms observed in either male or female B6C3F1/Nctr mice exposed to Usnea lichens. Histopathological changes were observed in the liver of males and in the liver and ovary of females. These were considered to be exposure-related and are summarized in Table 10. Significant hepatocellular degeneration, which was confined to the centrilobular region, was observed in the 360 ppm group in both males and females (Figure 7, Figure 8), but not at lower exposure. Significant atrophy of the ovary was observed in females in both the 180 and 360 ppm groups. These tissues were examined microscopically in progressively lower exposed groups until a NOAEL was reached at 180 ppm for males and 60 ppm for females (Appendix A).

Table 10 Statistical Analysis of Select Nonneoplastic Lesions in Male and Female Mice in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 15 ppm (2.5)^b^ | 30 ppm (5) | 60 ppm (10) | 180 ppm (30) | 360 ppm (60)
Males
Liver
Hepatocellular Degeneration
Overall rate^c^ | 0/10 (0.0%) | –^d^ | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate^e^ | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
CAFÉ p value^f^ | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity^g^ | – | – | – | – | – | 1.8
Females
Liver
Hepatocellular Degeneration
Overall rate | 1/10 (10.0%) | – | – | 0/10 (0.0%) | 1/10 (10%) | 8/9 (88.9%)
Terminal rate | 1/9 (11.1%) | – | – | 0/10 (0.0%) | 1/10 (10%) | 8/9 (88.9%)
CAFÉ p value | p ≤ 0.001 | – | – | p = 0.500N | p = 0.763 | p ≤ 0.001
Average severity | 2.0 | – | – | – | 1.0 | 1.6
Ovary
Atrophy
Overall rate | 1/10 (10.0%) | – | – | 0/10 (0.0%) | 7/10 (70.0%) | 10/10 (100.0%)
Terminal rate | 0/9 (0.0%) | – | – | 0/10 (0.0%) | 7/10 (70.0%) | 9/9 (100.0%)
CAFÉ p value | p ≤ 0.001 | | | p = 0.500N | p = 0.010 | p ≤ 0.001
Average severity | 2.0 | – | – | – | 1.9 | 2.5

^a^ Complete details of the dosing schedule are given in the methods section.

^b^ Denotes target dose as mg (+/−)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^d^ Indicates no data were collected.

^e^ Observed incidence at terminal sacrifice.

^f^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N. Significant p values are bolded.

^g^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 7

Section of the Liver from 0 ppm Male B6C3F1/Nctr Mice from the Three-month Feed Study of Usnea Lichens (H&E)

H&E = hematoxylin and eosin stain.

Figure 8

Section of the Liver from 360 ppm Male B6C3F1/Nctr Mice from the Three-month Feed Study of Usnea Lichens (H&E)

H&E = hematoxylin and eosin stain.

Serum creatinine concentrations were significantly elevated in female B6C3F1/Nctr mice exposed to either 180 or 360 ppm (+/−)-usnic acid in Usnea lichens and alkaline phosphatase activity, blood glucose and serum creatinine concentrations were elevated in male B6C3F1/Nctr mice exposed to 360 ppm (+/−)-usnic acid in Usnea lichens. Alanine aminotransferase values were not increased in either male and female mice exposed to 360 ppm Usnea lichens relative to control values despite the observed hepatocellular degeneration (Table C-2, Appendix C). There were no exposure-related changes in andrological parameters in male mice that indicated reproductive toxicity to Usnea lichens at the levels tested (Table G-3, Appendix G). However, in female mice, there was a moderate, statistically significant increase in estrous cycle length and estrus stage in the 360 ppm group that was probably exposure-related (Table G-4, Appendix G).

## Genetic Toxicology

Blood samples taken from mice exposed to Usnea lichens for 14 days were analyzed for erythrocyte and reticulocyte micronucleus formation as described in Appendix B. Lichen exposures containing 600 ppm of (+/−)-usnic acid significantly increased micronucleus frequency in reticulocytes from both male and female B6C3F1/Nctr mice.