# Materials and Methods

## Study Test Facility

The study was conducted between August 2008 and July 2009 under the U.S. Food and Drug Administration (FDA) 21 Code of Federal Regulations (CFR) Part 58, Good Laboratory Practices (GLP) conditions at the National Center for Toxicological Research (NCTR), 3900 NCTR Road, Jefferson, AR. The study followed NCTR policy relevant to this time period and utilized both F344/N Nctr rats and B6C3F1/Nctr mice, which were provided by the NCTR rodent breeding facility.

## Chemical Procurement and Characterization

Usnea lichens, typical of what is commercially available in the United States, were obtained from Mountain Rose Herbs, Inc. (Eugene, OR) in two bulk shipments, designated as lots 2074 and 4052. The crude Usnea lichen appeared to be stable; during the course of the study, samples of lot 2074 were stored for up to 3 years in sealed bags in the dark at 2°C–8°C, without visible changes to the lichen structure or significant changes in (+/−)-usnic acid content. The crude lichen was cleaned of leaf matter and other debris and examined microscopically and was identified as predominantly Usnea scabrata and U. cavernosa (Figure H-1, Appendix H), two Usnea species native to the United States, based on morphological characteristics.^3,77^ Both species contained similar concentrations of (+/−)-usnic acid (Table 2) and were combined in the final ground test article preparation.

Table 2 Recovery of Usnea scabrata and Usnea cavernosa from Bulk Usnea Lichens in the Three-month Feed Studies

| Batch 1 (Lot 2074) | Batch 2 (Lot 4052)
Total Weight | 3.166 kg | 1.301 kg
Usnea scabrata | 2.530 kg | 1.086 kg
(+/−)-Usnic acid content | [2.83%] | [2.14%]
Usnea cavernosa | 144 g | 15 g
(+/−)-Usnic acid content | [3.81%]^a^ | [3.81%]
Unknown Lichens | 91 g | 21 g
Other Material^b^ | 335 g | 152 g
Total Recovered | 3.100 kg | 1.274 kg
Lost^c^ | 66 g | 27 g

^a^ U. cavernosa from both batches were combined prior to analysis.

^b^ Predominantly tree bark, pine needles, and twigs.

^c^ Included reserve samples of 40 and 10 g, respectively, for the two batches and dust from the processing area that was removed with a vacuum cleaner.

Only the correctly identified U. scabrata and U. cavernosa lichens were prepared as the test article (Table 2). Batches of the material were hand ground under liquid nitrogen and sieved progressively into a fine powder. The usnic acid content of the sieved material from all batches was analyzed using high-performance liquid chromatography-photodiode array (HPLC-PDA) and found to be consistent. The batches were combined, homogenized in a blender, and re-analyzed for (+/−)-usnic acid. This final blended Usnea lichens preparation contained (+/−)-usnic acid at a concentration of 2.78% by weight, as determined by high-performance liquid chromatography (HPLC) after sequential extraction (Table 3, Appendix H). The average chiral composition of (+)-usnic acid and (−)-usnic acid was 97.5% ± 0.2 and 2.5% ± 0.2, respectively.

Table 3 Results of Analysis of (+/−)-Usnic Acid Content in Blended Usnea Lichens Powder Used in the Three-month Feed Studies

Sample^a^ | (+/−)-Usnic Acid Content mg/g (% by weight)
1 | 27.7 (2.77)
2 | 27.0 (2.70)
3 | 26.9 (2.69)
4 | 28.1 (2.81)
5 | 28.7 (2.87)
6 | 27.5 (2.75)
7 | 28.7 (2.87)
8 | 28.2 (2.82)
9 | 27.6 (2.76)
Mean | 27.8^b^ (2.78)

^a^ Batches 1 and 2 were combined prior to blending into the final test article used here.

^b^ Used to determine weight of lichen to be added to feed to provide required (+/−)-usnic acid ppm doses.

## Dose Formulation

Usnea lichens were incorporated in the NIH-41 irradiated meal chow by first grinding the Usnea lichens with the chow using a mortar and pestle, and then blending it in a mixer. For rats, ground lichen was added to feed to provide concentrations of 0, 30, 60, 120, 360, and 720 ppm (+/−)-usnic acid in feed. These concentrations were designed to provide target doses of 0, 2.5, 5, 10, 30, and 60 mg (+/−)-usnic acid/kg body weight/day (mg/kg/day), respectively, based on historical body weight and feed consumption data for the F344/N Nctr rat colony. The lichen concentrations in the dosed feed necessary to achieve the required doses of (+/−)-usnic acid are reported in Table F-5 (Appendix F) and ranged from 1,079 ppm to 25,899 ppm. For mice, ground lichen was added to feed to provide concentrations of 0, 15, 30, 60, 180, and 360 ppm (+/−)-usnic acid in feed. These concentrations were designed to provide target doses of 0, 2.5, 5, 10, 30, and 60 mg/kg/day based on historical body weight and feed consumption data for the B6C3F1/Nctr mouse colony. The lichen concentrations in the dosed feed necessary to achieve the required doses of (+/−)-usnic acid are reported in Table F-6 (Appendix F) and ranged from 540 ppm to 12,950 ppm. The (+/−)-usnic acid target doses used for both rats and mice were selected to match the doses of pure (+)-usnic acid previously used in a companion 3-month study.^76^ A preliminary 2-week toxicology study (Appendix J) confirmed that the rats and mice could tolerate acute exposure to the proposed doses. A sample from each preparation of each dose was analyzed for dose certification. In addition, homogeneity samples were collected from each preparation of the lowest dose level (15 ppm) and analyzed. Dosed feed was within 10% of target with a coefficient of variation (CV) < ± 10% (Table H-4). New preparations were prepared at least 14 days prior to the expiration of the preparation in use, or more frequently when required by the rate of consumption. Preparations were stored at 2°C–8°C until delivery to the animal rooms. Test article formulations in feed were determined to be stable in feed for at least 14 days at room temperature and up to 12 weeks at 2°C–8°C (Appendix H).

## Animal Breeding and Dosing

Animal exposure was conducted between February 18, 2009, and June 16, 2009. The study design followed guidelines as specified in the Specifications for the Conduct of Studies to Evaluate the Toxic and Carcinogenic Potential of Chemical, Biological and Physical Agents in Laboratory Animals for the National Toxicology Program (NTP).^78^ The Multigeneration Support System (MGSS) laboratory data system (designed and maintained by Z-Tech) was used to weight rank the animals according to NTP guidelines and to collect and maintain all in-life data on the study animals.

Male and female F344/N Nctr rats and male and female B6C3F1/Nctr mice were provided by the NCTR breeding colony and delivered at 3 weeks of age weighing approximately 35–50 grams for rats and 15–25 grams for mice. A total of 140 F344/N Nctr rats (70 males and 70 females) along with 140 B6C3F1/Nctr mice (70 males and 70 females) (Table 4) were delivered in five weekly shipments of 14 animals/sex/species for a total of 28 rats and 28 mice per shipment. Animals were acclimated in their designated animal room for a minimum of 10 days from date of receipt. At 7 weeks of age, the animals were weight ranked and randomized for the experiments by weight ranking. For each experiment, a total of 10 animals/sex/species were randomized to each of the six dose groups (Table 4); an additional 10 animals/sex were unassigned and considered extra. Due to the staggered exposures, two animals/sex/species were allocated to each of the six dose groups/study from each of the five weekly shipments (12 rats and 12 mice were allocated to the study per sex each week). The animals were randomized across the dose groups. At allocation, each animal received a three-digit tail tattoo (last three digits of the cage number). This tail tattoo was the physical link to the animal ID that was reflected when the cage was accessed by the MGSS system. The carcass identification number (CID)—composed of experiment/cage/test—was assigned to the animal and was used to track the animal through pathological evaluation.

Table 4 Experimental Design for the Three-month Feed Studies of Usnea Lichens in F344/N Nctr Rats and B6C3F1/Nctr Mice

Target Dose^a^ (Estimated mg/kg/day) | Feed Concentration for Rats^b,c^ (ppm) | Feed Concentration for Mice^b,c^ (ppm) | Number of Animals/Sex
0 | None | None | 10
2.5 | 30 | 15 | 10
5 | 60 | 30 | 10
10 | 120 | 60 | 10
30 | 360 | 180 | 10
60 | 720 | 360 | 10
0 | Sentinel^d^ | Sentinel^d^ | 2^e^

^a^ Target dose estimate was calculated from historical body weight and feed consumption data for the animal colonies.

^b^ Feed concentrations are denoted by their (+/-)-usnic acid content as ppm added to feed.

^c^ Doses were selected based on data obtained from 14-day feed studies (Appendix J) and historical data for the animal colonies.

^d^ Sentinel animals received control feed.

^e^ Sentinel animals were female only.

One unallocated animal from the first shipment of each species and one unallocated animal from the fourth shipment of each species were assigned to the study as sentinels (total two rats and two mice). One sentinel from each species was removed on week 13 of the study and the other sentinel was removed on week 17 of the study. In-life data collection for sentinel animals included body weights and observations for mortality and morbidity daily. Daily observations for all animals, including sentinels, were conducted at morning and afternoon morbidity/mortality checks. After removal, the sentinels were sent for microbiological evaluation.

## Animal Husbandry

Animal husbandry was performed per NTP guidelines.^78^ Microbiological surveillance samples were collected by the animal care staff from the animal room(s) and analyzed. The environments of the animal rooms were continually monitored. Environmental controls were set to maintain the temperature at 22°C ± 4°C, with a relative humidity of 40%–70%. A 12-hour light/dark cycle was maintained. The animal rooms received 10–15 air changes per hour.

The test animals were fed irradiated NIH-41 ground feed ad libitum and filtered tap water was provided ad libitum. NIH-41 is an irradiated form of the NIH-31 diet and is the standard diet for rodent bioassays at NCTR that use F344/N Nctr rats and B6C3F1/Nctr mice. Its use was required so that animal data could be compared with the historical database. Animal body weights were recorded twice weekly, and feed consumption was recorded weekly. Cages were changed once a week. Water bottles from the animal rooms were analyzed for microbiological contamination at start of dosing and during weeks 13 and 17.

Dead and moribund animals were removed from the study. Cage racks were washed every 4 weeks. Both rats and mice were singly housed. Hardwood chips (Northeastern Products Corp., Warrensburg, NY) were used as cage bedding and were autoclaved prior to use on the studies to preclude contamination at levels that would interfere with the studies. Random samples for this analysis of the autoclaved bedding were analyzed to monitor microbial load.

## Necropsy and Histopathology

A gross examination was performed on all animals at the completion of each individual 3-month dosing schedule, and on those that died during the experiment or were removed for other reasons. These examinations were conducted under the supervision of a pathologist.

On the afternoon before a scheduled terminal sacrifice, the animals were weighed and delivered to the necropsy holding area. The animals were fasted overnight but had access to water. On the necropsy day, all animals were weighed and then anesthetized with carbon dioxide (>99% in accordance with American Veterinary Medical Association guidelines). A cardiac puncture was performed to collect blood for clinical pathology analyses of the following parameters: red and white blood cells, hemoglobin content, platelets, hematocrit, mean cell hemoglobin concentration, mean cell volume, glucose, total protein, albumin, creatine kinase, phosphorus inorganic, alanine aminotransferase, alkaline phosphatase, urea nitrogen, and creatinine. The animals were then euthanized by exposure to carbon dioxide. Further details of animal maintenance are summarized in Table 5.

Table 5 Experimental Design and Materials and Methods in the Three-month Feed Studies of Usnea Lichens

Three-month Studies
Study Laboratory
U.S. FDA National Center for Toxicological Research (NCTR, Jefferson, AR)
Strain and Species
Rats: F344/N Nctr
Mice: B6C3F1/Nctr
Animal Source
NCTR breeding colony
Time Held before Studies
10 days
Average Age When Studies Began
8 weeks
Date of First Exposure (Staggered Loading)
Rats: February 18, 25, March 04, 11, 18, 2009
Mice: February 17, 24, March 03, 10, 17, 2009
Duration of Exposure
3 months
Date of Last Exposure (Staggered Loading)
Rats: May 19, 26, June 02, 09, 16, 2009
Mice: May 18, 25, June 01, 08, 15, 2009
Necropsy Dates (Staggered Loading)
Rats: May 20, 27, June 03, 10, 17, 2009
Mice: May 19, 26, June 02, 09, 16, 2009
Average Age at Necropsy
21 weeks
Size of Study Groups
Rats: 60 males and 62 females
Mice: 60 males and 62 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial body weights.
Animals per Cage
Rats: 1
Mice: 2 (divided)
Method of Animal Identification
Rats: tail tattoo
Mice: tail tattoo
Diet
Irradiated rodent chow (Harlan Teklad, Madison, WI) (also designated NIH-41 IR), available ad libitum
Water
Filtered tap water (Jefferson Laboratories potable water supply, monitored monthly for bacteriological quality and quarterly for state health criteria), available ad libitum
Cages
Polycarbonate cages (Lab Products, Inc., Seaford, DE, and Allentown Caging Equipment Co., Inc., Allentown, NJ), changed once weekly
Bedding
Autoclaved hardwood chip bedding (Northeastern Products Corp., Warrensburg, NY), changed twice weekly (rats) or once weekly (mice)
Cage Filters
MicroVENT cage filtration with 0.2 micron HEPA filter (Allentown Caging Equipment Co., Inc., Allentown, NJ), changed weekly
Racks
Stainless steel (Allentown Caging Equipment Co., Inc., Allentown, NJ), changed every 4 weeks
Animal Room/Chamber Environment
Temperature: 22°C ± 4°C
Relative humidity: 40%–70%
Room fluorescent light: 12 hours/day
Room air changes: 10–15/hour
Exposure Concentrations
Rats: 0, 30, 60, 120, 360, and 720 ppm (+/-)-usnic acid
Mice: 0, 15, 30, 60, 180, and 360 ppm (+/-)-usnic acid
Type and Frequency of Observation
Observed twice daily; animals weighed twice weekly; feed and water consumption measured weekly
Method of Euthanasia
Carbon dioxide (>99%)
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, left kidney, liver, lung, right testis, left testis, right epididymis, left epididymis, and thymus; organs were not weighed for dead animals; only liver and lung weighed for moribund animals.
Clinical Pathology
Blood was collected via cardiac puncture during euthanasia
Hematology: erythrocyte cell count, hematocrit, hemoglobin, mean cell volume, mean cell hemoglobin, mean cell hemoglobin concentration, leukocyte cell count, and platelet count
Clinical Chemistry: glucose, total protein, albumin, creatine kinase, phosphorus inorganic, alanine aminotransferase, alkaline phosphatase, urea nitrogen, and creatinine
Histopathology
Histopathology was performed on all animals from the control and high exposure groups with a read-down approach and all gross lesions. The following tissues were examined: adrenal cortex, bone with marrow, brain, clitoral glands, epididymis, esophagus, eyes, femur, gallbladder (mouse), gross lesions, Harderian glands, heart and aorta, intestine, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidneys, liver, lungs, lymph nodes (lumbar, mandibular, and mesenteric), mammary gland, muscle (thigh), nasal cavity and nasal turbinates, ovaries, pancreas, parathyroid glands, pharynx, pituitary gland, preputial glands, prostate gland, salivary glands, seminal vesicle, skin, spinal cord, spleen, stomach, testis, thymus, thyroid gland, trachea, urinary bladder, uterus, and Zymbal’s gland.
Sperm Motility and Vaginal Cytology
The left testis, left cauda, and left epididymis from males in three dosed groups and the control group (rats: 0, 60, 120, and 360 ppm; mice: 0, 60, 180, and 360 ppm) were evaluated for percent motile sperm, number of sperm/mg cauda, total number of sperm/cauda, number of homogenization-resistant spermatids/mg testis, and total number of spermatids/testis. Vaginal lavage samples from females in three dosed groups and the control group (rats: 0, 60, 120, and 360 ppm; mice: 0, 60, 180, and 360 ppm) were collected for 16 consecutive days prior to the end of the studies for estrous cycle evaluation.

Complete necropsies were performed on each animal in all dose groups in all studies. Heart, right kidney, left kidney, liver, lung, right testis, left testis, right epididymis, left epididymis, and thymus weights were taken on terminal sacrifice animals. Liver and lung weights were taken on moribund animals. No weights were taken on early death animals. All gross lesions were recorded to include number, location, size, and color, as appropriate.

Organs and tissues were fixed in 10% neutral buffered formalin and then processed to paraffin blocks or slides for histopathological examination using a read-down approach. Histological sections of <6 µm in thickness were prepared, fixed, and stained with hematoxylin and eosin. Eyes and right testes and epididymides were fixed in modified Davidson's fixative. The left testes were frozen in liquid nitrogen and stored at −80°C for spermatid evaluation. Liver tissues for histopathologic evaluation had a specified fixation time of 48 hours due to immunohistochemistry requirements.

A reproductive toxicity assessment on animals was conducted according to NTP Specifications,^78^ with modifications. All male mice from the vehicle control, 60, 180, and 360 ppm (+/−)-usnic acid groups (40 mice total) were evaluated for sperm count and sperm motility. All male rats from the vehicle control, 60, 120, and 360 ppm groups (40 rats total) were evaluated for sperm count and sperm motility since all male rats from the 720 ppm group were removed from the study early. All female mice from the vehicle control, 60, 180, and 360 ppm (+/−)-usnic acid groups (40 mice total) were evaluated for estrous cycling activity via cytological examination of vaginal lavage samples collected daily for 16 consecutive days preceding necropsy (i.e., vaginal cytology). All female rats from the vehicle control, 60, 120, and 360 ppm groups (40 rats total) were evaluated for estrous cycling activity via cytological examination of vaginal lavage samples collected daily for 16 consecutive days preceding necropsy.

Sperm count and sperm motility were conducted on the left epididymis (cauda). Vaginal lavage was conducted in the animal room. The fixed vaginal cytology slides and frozen testes were shipped to NTP’s contract laboratory for evaluation. Samples of sperm suspension from the left epididymis (cauda) were shipped to the National Institute of Environmental Health Sciences/NTP Tissue Repository.

## Statistical Methods

Statistical analyses were performed on body weights, mean daily feed consumption (calculated from the weekly [rats] or twice weekly [mice] feeder weights, for each week of the 13 weeks of dosing), water consumption (calculated from the individual [rats] or shared [mice] water bottle weights, for each week of the 13 weeks of dosing), organ weights, clinical chemistry, hematology, and survival. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Under the assumption of normally distributed data, trend tests used linear regression, and comparisons of exposed groups to control were performed with Dunnett’s method for adjusted contrasts.^79^ The probabilities of survival were estimated by the product-limit procedure of Kaplan and Meier.^80^ Animals found dead of other than natural causes were censored from the survival analyses.^81-84^

Analysis of continuous variables for clinical chemistry and mutagenicity data were conducted using a linear regression trend test, with Dunnett’s test^79^ used to compare the dosed group means with the vehicle control means. The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with dose.^85,86^ Fisher’s exact test was used to compare incidences between exposed groups and the control group.^87^ Tests for trend and comparisons of exposed groups to control were performed as one-sided tests.^88^

Sperm counts and estrous cycle lengths were analyzed using the nonparametric multiple comparison methods of Shirley (as modified by Williams) and Dunn. Necropsy body weights and organ weights that were evaluated as part of the reproductive tissue analysis were analyzed using the parametric multiple comparison methods of Williams and Dunnett. Jonckheere’s test^89^ was used to assess the significance of the exposure-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (Shirley’s or Williams’ test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure-related trend (Dunn’s or Dunnett’s test).^90^ Estrous cyclicity data were also analyzed using a Markov transition matrix approach^91^ in which exposure effects were investigated by testing for increased probabilities for deviations in cycling relative to the vehicle control group using the Chi-square Test.

## Quality Assurance Methods

These 3-month studies were conducted in compliance with FDA GLP Regulations (21 CFR, Part 58). In addition, records from these studies, including protocol and any amendments, deviations, or related information; study-related standard operating procedures and documentation; test article accountability and characterization; raw data generated in operational areas as defined in applicable standards of practice; computer records containing in-life and pathology raw data; daily animal room logs; and the NCTR final report are maintained in the NCTR Archives.