# Introduction

Figure 1

Usnea Lichens (CASRN 125-46-2 [(+/−)-Usnic acid]; Chemical Formula: C_18_H_16_O_7_; Molecular Weight: 344.32)

Synonyms: Usnea barbata; U. scabrata; U. cavernosa; U. longissima; U. species. Trade names: Usnea extract, usnic acid extract, Usnea barbata, Usnea moss.

## Chemical, Botanical, and Physical Properties

Lichen species of the Usnea genus that have been used in traditional medicine are commonly known as beard lichens due to their characteristic pendulous growth from tree branches.^1,2^ Lichens are stable symbiotic associations between fungi and algae/cyanobacteria.^3^ The lichen algal cells, which can be either eukaryotic green algae, cyanobacteria, or a mixture of both and are described as photobionts or cyanobionts, respectively, provide organic nutrients via photosynthesis. The fungal cells, described as mycobionts, contribute water, nutrients, and gases to the organism and also produce several classes of chemicals called lichen secondary metabolites.^3,4^ Lichen species are designated by the mycobiont because individual species of algae can associate with many different fungal species. Lichens are estimated to cover approximately 8% of the Earth’s land surface and there are over 28,000 species of lichens worldwide with the majority growing in tropical regions.^5-7^ The majority of lichenized fungi belong to the order Lecanorales, which comprises 20 families, and the genus Usnea belongs to Parmeliaceae, which is the largest family of lichen-forming ascomycetes.^3,7^ Over 350 Usnea species have been identified worldwide, but only a relatively small number of these have the pendant, filamentous morphology of beard lichens. Of these, the beard lichen species most commonly listed in European traditional medicine texts are U. barbata, U. hirta, U. longissima, and U. plicata.^1,8^ In East Asia, U. aciculifera, U. diffracta, U. longissima, U. siamensis, and U. undulate species are the most common beard lichens.^8-10^ In North America, common beard lichen species of Usnea include: U. cavernosa, U. dimorpha, U. diplotypus, U. flipendula, U. hespernia, U. longissima, U. scabrata, U. strigosa, U. subscabrosa, and U. trichodea.^3^ However, certain lichens belonging to other genera are sometimes mistaken for Usnea lichens due to similar external morphology. For example, Alectoria sarmentosa (Witch’s hair lichen) also grows in pendulous strands in similar habitats to Usnea beard lichens, but unlike Usnea species, Alectoria lichens do not have a flexible string-like central core within the pendant lichen thallus.^3^

Lichen secondary metabolites generally have phenolic structures and include depsidones, depsides, dibenzofuranes, depsones, quinones, pulvinic acid derivatives, sterols, and terpenoids.^11,12^ When Usnea species contain high concentrations of certain secondary metabolites, their presence can be detected by spot tests or thin-layer chromatography of crude extracts, which aid in the identification of the species.^3,13^ Consequently, botanical keys and classification studies list only the major secondary metabolites present in a species. However, modern extraction and chemical analytical techniques have identified lower concentrations of many more metabolites in most Usnea species. For example, Prateeksha and coworkers^14^ have recently listed over 70 secondary metabolites and bioactive compounds that have been reported to have been isolated from Usnea species. While most botanical keys list only (+)-usnic and salazinic acids as secondary metabolites present in U. barbata or its North American subspecies U. scabrata,^3,15^ Salgado and coworkers^16^ detected 44 peaks using liquid chromatography–mass spectrometry from a methanolic extract of a lichen identified as U. barbata that was collected in Chile. Of these, 34 were identified mainly as depsides, depsidones, lipids, diphenyl ether derivatives, and dibenzofurans.^16^ The dibezofurane, (+/−)-usnic acid was the most abundant peak identified despite having low solubility in alcohols.^17,18^ (+)-Usnic acid is generally the most abundant and pharmacologically important secondary metabolite in Usnea species and can constitute up to 3% of lichen dry weight.^3,12^ Biologically significant secondary metabolites (Table 1) that have been reported to be present in multiple Usnea beard lichen species include atranorin, barbatic acid, barbatolic acid, diffractaic acid, evernic acid, galbinic acid, norstictic acid, salazinic acid, squamatic acid, stictic acid, and (+)-usnic acid.^12,14,16^ The secondary metabolite profile of a Usnea species can differ both quantitatively and qualitatively due to environmental factors, including light intensity, UV exposure, elevation, temperature fluctuations, humidity, and seasonality.^19^

Table 1 Major Secondary Metabolites Present in Usnea Beard Lichen Species

Metabolite | Structure
Atranorin: C_19_H_18_O_8_ 374.34 (CASRN 479-20-9), IUPAC name: (3-hydroxy-4-methoxycarbonyl-2,5-dimethylphenyl) 3-formyl-2,4-dihydroxy-6-methylbenzoate. [Depside: Present in U. aciculifera, U. barbata.]
Barbatic acid: C_19_H_20_O_7_ 360.35 (CASRN 17636-16-7), IUPAC name: 2-hydroxy-4-(2-hydroxy-4-methoxy-3,6-dimethyl-benzoyl)oxy-3,6-dimethyl-benzoic acid. [Depside: Present in U. barbata, U. longissima.]
Barbatolic acid: C_18_H_14_O_10_ 390.19 (CASRN 529-50-0), IUPAC name: 3-formyl-2,4-dihydroxy-6-methylbenzoic acid (2-carboxy-4-formyl-3,5-dihydroxyphenyl)methyl ester. [Depside: Present in U. barbata.]
Diffrataic acid: C_20_H_22_O_7_ 374.38 (CASRN 436-32-8), IUPAC name: 4-(2,4-dimethoxy-3,6-dimethylbenzoyl)oxy-2-hydroxy-3,6-dimethylbenzoic acid. [Depside: Present in U. aciculifera, U. barbata, U. diffracta, U. longissima.]
Evernic acid: C_17_H_16_O_7_ 332.30 (CASRN 537-09-7), IUPAC name: 2-hydroxy-4-(2-hydroxy-4-methoxy-6-methylbenzoyl)oxy-6-methylbenzoic acid. [Depside: Present in U. barbata, U. longissima.]
Galbinic acid: C_17_H_16_O_7_ 332.30 (CASRN: unlisted), alternate name: α-Acetylsalazinic acid. [Depsidone: Present in U. barbata, U. undulate.]
Norstictic acid: C_18_H_12_O_9_ 372.28 (CASRN 571-67-5), IUPAC name: 1,4,10-trihydroxy-5,8-dimethyl-3,7-dioxo-1,3-dihydro-7H-2,6,12-trioxabenzo[5,6]cyclohepta[1,2-e]indene-11-carbaldehyde. [Depsidone: Present in U. aciculifera, U. barbata, U. undulate.]
Salazinic acid: C_18_H_12_O_10_ 388.28 (CASRN 521-39-1), IUPAC name: 1,4,10-trihydroxy-5-(hydroxymethyl)-8-methyl-3,7-dioxo-1,3-dihydro-7H-2,6,12-trioxabenzo[5,6]cyclohepta[1,2-e] indene-11-carbaldehyde. [Depsidone: Present in U. aciculifera, U. barbata, U. diffracta, U. longissima, U. scabrata, U. undulate.]
Squamatic acid: C_19_H_18_O_9_ 390.33 (CASRN 569-36-8), IUPAC name: 4-(3-carboxy-2-hydroxy-4-methoxy-6-methylbenzoyl)oxy-2-hydroxy-3,6-dimethylbenzoic acid. [Depside: Present in U. longissima.]
Stictic acid: C_19_H_14_O_9_ 386.30 (CASRN 549-06-41), IUPAC name: 4-dihydroxy-10-methoxy-5,8-dimethyl-3,7-dioxo-1,3-dihydro-7H-2,6,12-trioxabenzo[5,6]cyclohepta[1,2-e]indene-11-carbaldehyde. [Depsidone: Present in U. barbata.]
(+/−)-Usnic acid: C_18_H_16_O_7_, 344.31 (CASRN 125-46-2 for racemic mixture), IUPAC name: 2,6-diacetyl-7,9-dihydroxy-8,9b-dimethyl-1,3(2H,9bH)-dibenzofurandione. Enantiomers (+)-(12R)-usnic acid (CASRN 7562-61-0) and (−)-(12S)-usnic acid (CASRN 6159-66-6) have both been reported to be present in Usnea species, but (+)-usnic acid enantiomer predominates. [Dibenzofuran: Present in all Usnea species.]

(+)-Usnic acid (CASRN 7562-61-0) is by far the most studied secondary metabolite of Usnea lichens and has been attributed as responsible for most of the pharmacological properties of these lichen species.^2,20^ It is highly lipophilic in both neutral and anionic forms due to its β-triketone groups, which absorb the negative charge of the anion by resonance stabilization.^21^ This lipophilicity of (+)-usnic acid and the usniate anion allows (+)-usnic acid to behave as a membrane uncoupler in a manner similar to that of 2,4-dinitrophenol.^22-24^ This uncoupling activity of pure (+)-usnic acid has been demonstrated in mitochondria in several in vitro studies,^25-28^ and is thought to play a major role in (+)-usnic acid-induced hepatotoxicity. However, (+)-usnic acid also produces the same uncoupling actions on bacterial cell membranes, and this forms the basis for its antimicrobial activity.^24^ (−)-Usnic acid shows similar, but not identical, pharmacological and toxicological activity and also can be present in low concentrations in Usnea lichen specimens so that usnic acid in Usnea lichen extracts should be classified as the racemic mixture, (+/−)-usnic acid (CASRN 125-46-2), even though (+)-usnic acid will usually be the predominant enantiomer present.

## Production, Use, and Human Exposure

Traditionally, Usnea species, such as the pendulous “beard” lichens U. barbata, U. florida, and U. longissima, have been used in Eurasia, Africa, and the Americas as a source of usnic acid in herbal medicine.^1,14,20,29^ The first recorded use of an Usnea species known as “Song Lo” in traditional Chinese medicine dates to 101 BC.^30^

Song Lo has been identified as U. longissima and, according to current texts on Chinese herbal medicine, it is still used together with Lao-Jun-Xu (Lao Tzu’s beard, or pine gauze, U. diffracta) as a treatment for many conditions including headache, ocular irritation, cough, profuse phlegm, malaria, external wound bleeding, and snake bites.^8,31^ Suggested oral doses range from 6 to 9 grams daily, which would provide approximately 60–120 mg (+/−)-usnic acid per day.^8,31^ U. siamensis (Foi-lom) is used in Thailand as a traditional treatment for ailments similar to those in China.^32^ In Europe, U. barbata is sold in tinctures for use mainly as an antimicrobial.^2,30^ The powdered lichen itself has also been used to directly treat burns and open wounds.^2,30^

Usnea is sold in the United States as alcoholic tinctures, capsules, tea bags, or bulk dried herb and is usually named wildcrafted “Usnea Lichen,” “Usnea Lichen Moss,” or “Usnea Barbata.” However, the latter, if truly wildcrafted from local species, is unlikely to be U. barbata as this species is not native to North America.^3,33^ Wildcrafted North American lichen products are more likely to consist of U. cavernosa, U. filipendula, U. longissima, or U. scabrata, which are morphologically similar to Eurasian U. barbata and all contain predominantly (+)-usnic acid.^3,15^ U. scabrata is the North American species most closely related to U. barbata.^15^ In addition, lichens from other genera such as Alectoria sarmentosa (Witch’s Hair lichen), which contain predominantly (−)-usnic acid, can be mistaken for Usnea.^3,12^ Tinctures continue to be the most commonly marketed form of Usnea lichens and recipes are available in the herbal literature explaining how these can be made at home using wildcrafted lichen.^34^

Because of (+/−)-usnic acid’s bright yellow color, Usnea and other usnic acid-containing lichens were extensively used as a fabric dye for many years in Europe prior to the advent of synthetic aniline dyes.^5^ (+/−)-Usnic acid was first isolated from Usnea lichens in 1843 and, although it has since been chemically synthesized, Usnea lichens still remain the primary commercial source of pure (+)-usnic acid.^2^ (−)-Usnic acid has not been commercially available in large quantities until recently when a venture in Norway started extracting it from Cladonia stellaris (reindeer moss),^35^ which covers vast areas of arctic tundra and is therefore more abundant than Usnea lichens, which are threatened by habitat loss, particularly in North America.^36^ It is possible, therefore, that in the future (−)-usnic acid will become the predominant usnic acid enantiomer used in herbal and pharmaceutical preparations.

## Pharmacology

### Antimicrobial Activity

Interest in Usnea lichens and their secondary metabolites, such as (+)-usnic acid, as antimicrobials has increased in North America since the advent of antibiotic-resistant bacteria and increased availability of herbal medicines following the passage of the Dietary Supplement Health and Education Act of 1994.^20,30^ Although recent research has mainly focused on investigating the established antimicrobial activity of pure (+)-usnic acid against Gram-positive bacteria,^2,20,30,37^ Usnea lichen extracts also have been tested. Cansaran and coworkers^29^ tested acetone extracts of six lichen species (U. barbata, U. florida, U. hirta, U. longissima, U rigida, and U. subflorida) for antibacterial activity against several bacterial strains. The U. subflorida extract exhibited the greatest potency in inhibiting the growth of Bacillus species and the potency of each species correlated with their extract’s (+/−)-usnic acid content. A study from Oregon State University reported that extracts of U. filipendula containing (+/−)-usnic and salazinic acids inhibited the growth of Salmonella gallinarum in addition to Gram-positive bacteria and postulated that the two lichen acids might work synergistically against this Gram-negative bacteria.^13^ Bazarnova and coworkers^38^ recently reported that a 1,4-dioxane extract of U. barbata collected in northern Russia inhibited the growth of both Gram-positive B. subtilis and Gram-negative Pseudomonas fluorecens. The extract contained (+/−)-usnic acid equivalent to 2.4% of lichen dry weight as well as several other lichen secondary metabolites. A Brazilian study reported that diffractaic acid and (+/−)-usnic acid extracted from U. subcavata, a local Usnea species, were active against Mycobacterium tuberculosis.^39^ Extracts of another Brazilian lichen, U. steineri, has also shown activity against M. tuberculosis, M. avium, and M. kansasii.^40,41^ In traditional Chinese medicine, recommended doses of U. longissima or U. diffracta are listed as 6–9 g per day, which corresponds to 60–120 mg of (+/−)-usnic acid per day. However, Frankos^30^ reported that a 1970s-era Encyclopedia of Chinese Materia Medica listed 30 g of Song Lo per day for 10 days as a standard treatment for chronic bronchitis, suggesting that doses of up to 300 mg (+/−)-usnic acid were required for successful clinical efficacy. In contrast, U.S. herbalists recommend Usnea lichen tinctures (20% dry lichen) at a maximum dose of 6 teaspoons (29.6 mL or 6 g lichen) per day to treat antibiotic-resistant Gram-positive bacterial infections potentially providing up to 120 mg (+/−)-usnic acid per day if all the lichen’s (+/−)-usnic acid is extracted into the tincture.^34^

### Antimycotic Activity

Methanol extracts of U. siamensis were reported to inhibit growth of Candida guilliemendii, but not C. albicans.^42^ However, pure (+)-usnic acid, isolated from lichen extracts and identified by infrared spectroscopy and polarimetry, was reported to inhibit growth of C. albicans and C. glabrata with minimal inhibitory concentrations of 2 μM.^43^ In another study, acetone and ethyl acetate extracts of U. complanata that contained significant concentrations of (+/−)-usnic and psoromic acids were reported to be active against 11 fungal strains including Aspergillus niger and C. albicans.^44^

### Antiviral Activity

In a cancer chemoprevention assay, extracts of Usnea longissima thallus were found to be significantly effective against tumor-promoter-induced Epstein-Barr virus.^45^ The constituent secondary metabolites—(+)-usnic acid, barbatic acid, diffractaic acid, 4-O-demethylbarbatic acid, and evernic acid—all inhibited Epstein-Barr virus activation, but (+)-usnic acid was the most potent inhibitor with a median effective dose (ED_50_) of 1.0 μg/mL.^45^

### Antiproliferative Activity

In a recent U.S. study,^46^ an ethanol extract of U. strigosa (bushy beard lichen) inhibited growth of a breast cancer cell line, MDA-MB-231 in vitro. Norstictic acid was identified as the active metabolite, which appeared to inhibit MDA-MB-231 cell proliferation, migration, and invasion in the μM concentration range, with minimal toxicity to nontumorigenic MCF-10A mammary epithelial cells. Norstictic acid also reduced the size and proliferation rate of MDA-MB-231 xenograft tumors when administered to the athymic murine hosts at a dose of 15 mg/kg intraperitoneally (i.p.) three times per week.^46^ (+)-Usnic acid caused moderate inhibition in the murine P388 leukemia assay and exhibited cytotoxic activity against cultured L1210 cells; the p-tri-ketone moiety was inferred to be essential for the optimum activity.^47^ (+)-Usnic acid (50 μg/mL) reduced the cell counts of leukemic (K-562) and endometrial (Ishikawa and HEC-50) carcinoma cell cultures.^23,48^ (+)-Usnic acid exhibited cytotoxic activity against human keratinocyte cell cultures.^49^

### Anti-inflammatory Activity

The phenolic secondary metabolite, longissiminone A, isolated from U. longissima, has been reported to exhibit moderate anti-inflammatory activity in both a human neutrophil-based in vitro assay^50^ and in a rat paw edema test, in which the effect of longissiminone A was comparable on a weight basis to that of aspirin.^51^

### Analgesic and Antipyretic Activity

In a study using mice, the analgesic and antipyretic effects of a methanol extract of U. diffracta containing (+/−)-usnic and diffractaic acids, identified by thin-layer chromatography, were evaluated.^52^ Oral doses of 500 mg/kg produced a significant analgesic effect as indicated by an acetic acid-induced writhing test, whereas higher doses produced marked hypothermia and were fatally toxic for up to a third of the animals. (+/−)-Usnic and diffractaic acid were isolated from the extract and both exhibited significant analgesic activity at oral doses of 100 and 200 mg/kg, respectively. In a European study, a supercritical CO_2_-extract from U. barbata containing 4% (w/w) (+/−)-usnic acid was reported to inhibit ultraviolet-B induced prostaglandin E2 synthesis and COX-2 expression in HaCaT keratinocytes in vitro over a concentration range of 19–312 mg/mL.^53^

## Absorption, Distribution, Metabolism, and Excretion

No information was found in the literature on whether the absorption or metabolism of (+/−)-usnic acid in crude lichen extract differs from that of the pure (+)-usnic acid. The pharmacokinetics of (+)-usnic acid were studied in rabbits following intravenous or oral administration of 5 or 20 mg (+)-usnic acid per kg body weight (mg/kg), respectively.^54^ Plasma (+)-usnic acid levels following intravenous administration showed a tri-exponential elimination with a terminal half-life of 10.7 ± 4.6 hours. The volumes of distribution of the central compartment and systemic clearance were 43.9 ± 21.3 mL/kg and 12.2 ± 3.0 mL/hr/kg, respectively. Peak plasma level (C_max_) of 32.5 ± 6.8 μg/mL was achieved in 12.2 ± 3.8 hours (t_max_). The mean absolute bioavailability of (+)-usnic acid following oral administration was 77.8%. Plasma (+)-usnic acid was highly protein-bound.^55^ In rats treated i.p. with 25 mg/kg (+)-usnic acid, it accumulated in the liver and lungs at levels similar to plasma concentrations, but accumulated at lower concentrations in brain, fat, testes, and other organs.^55^ No pharmacokinetic studies were found for other Usnea lichen secondary metabolites.

## Toxicity

### Experimental Animals

Dobrescu et al.^56^ evaluated a pooled extract of U. barbata and U. hirta collected in Romania for acute toxicity in mice. The ground lichen material was extracted with 67.3% ethanol in water over 3 weeks and then filtered to produce a standardized tincture. This tincture was then concentrated and buffered to pH 7–8 for the evaluation. No toxicity was observed in mice following single oral gavage doses up to 32 g of original lichen material per kg body weight (g/kg). The reported median lethal dose (LD_50_) values for i.p. and i.v. dosing were 22.5 g/kg and 7.4 g/kg, respectively.^56^ A recent Chinese study evaluated the effects of extracts of U. diffracta on lipid profiles and hepatotoxicity biomarkers in rats that were fed a high-fat diet.^57^ After being acclimatized to a high-fat diet for 45 days, male and female Sprague Dawley rats were dosed via oral gavage with either an aqueous or an ethanol extract of the powdered lichen for 21 days at doses of 2.77 g/kg/day. Both U. diffracta extracts significantly decreased serum alanine aminotransferase (ALT), aspartate aminotransferase (AST), and triglyceride and total cholesterol concentrations compared to control animals fed the high-fat diet. Histopathological evaluation of the livers from these rats showed marked steatosis and accumulation of fat droplets compared to rats fed a normal diet. Exposure to both U. diffracta extracts appeared to decrease the severity of steatosis without causing observable hepatocellular degeneration.^57^

Acute toxicity studies of pure (+)-usnic acid have been reported for both animals and plants. In several experimental animal or wild animal species, such as guinea pigs, mice, rats, domestic sheep, cow elks, and mosquitoes, either general toxicity or organ-specific toxicity, or both, have been reported. In female guinea pigs with tuberculosis, subcutaneous injection of usnic acid (enantiomer not recorded, 20 mg per animal for 6 days, followed by 10 mg per animal for 24 days) caused a slight weight loss in the first week and a significant inhibition of weight gain during the next 3 weeks.^58^ Even after the discontinuation of usnic acid, weight gain was still reduced 44%–68% for at least 2 weeks. This report was the first that showed that usnic acid could cause weight loss with the possibility of general toxicity, though potential toxicity was largely ignored in the ensuing decades. Of note, no apparent organ-specific toxicities in the liver, spleen, or lung were reported and no therapeutic effects were observed.^58^ In healthy male Swiss mice, treatment with pure (+/−)-usnic acid that was isolated from a Cladonia lichen species, at a dose of 15 mg/kg (i.p.) for 15 days caused no apparent general toxicity, as evidenced by the negative observations of clinical signs or changes in body weight.^59,60^ However, strong hepatotoxicity including elevated serum transaminase activity and extensive liver necrosis were observed. No toxicity in other organs such as the kidney and spleen were detected in the study. A similar pattern of toxicity was also revealed in the tumor-bearing mice.^59,60^ In male Wistar albino rats, (+)-usnic acid isolated from U. siamensis (i.p., 50 or 200 mg/kg for 5 days), induced remarkable swelling of the liver mitochondria and endoplasmic reticulum assessed by electron microscopy. However, no changes in serum transaminase activity were observed, indicating that mild hepatotoxicity occurred.^27^ Another study using Wistar albino rats reported that oral administration of 500 or 1,000 mg/kg (+/−)-usnic acid, isolated from U. longissima, did not produce toxic effects after 24 hours, but exposure to 2,000 mg/kg showed some toxicity.^61^ Feeding domestic sheep with 98% pure (+)-usnic acid at 323–776 mg/kg/day for a maximum of 9 days induced several clinical signs such as lethargy and anorexia, or even death, with the estimated median toxic dose between 485 and 647 mg/kg/day.^62^ Other toxicity indices such as serum lactate dehydrogenase, aspartate aminotransferase, and creatine kinase were also increased. A complete postmortem examination revealed that pathological changes occurred exclusively in the skeletal muscle.^62^ This observation contrasts sharply with mice, rats, and humans, in which the liver is considered the primary target organ for oral toxicity of (+)-usnic acid.

#### Subchronic Toxicity Studies

No subchronic animal studies were found in the literature.

#### Chronic Toxicity Studies

Extensive library searches (Frankos,^30^ updated in 2017) did not provide any information on chronic studies of Usnea lichens or (+/−)-usnic acid.

### In Vitro

In vitro toxicity studies have focused on (+)-usnic acid rather than on Usnea lichen extracts. Uncoupling of oxidative phosphorylation by (+)-usnic acid was confirmed in mouse liver mitochondria by Abo-Khatwa et al.^25^ Concentrations as low as 0.75 μM (+)-usnic acid decreased the phosphate/oxygen ratio dramatically, without inhibition of oxygen consumption. Stimulation of oxygen consumption by (+)-usnic acid was observed in the presence of the adenosine 5’-triphosphate (ATP) synthase inhibitor oligomycin, confirming that usnic acid was acting to uncouple oxidative phosphorylation. Interestingly, approximately 10× the concentration of the classic uncoupler 2,4-dinitrophenol was required to reproduce the level of uncoupling produced by the usnic acid exposure.

A more recent study using (+)-usnic acid purified from U. siamensis^27^ using isolated rat liver mitochondria demonstrated that concentrations as low as 0.3 μM could significantly increase ATPase activity and oxygen consumption. The same study showed that in isolated rat hepatocytes, (+)-usnic acid also stimulated markers of lipid peroxidation, but that much higher concentrations were required (100 μM). These effects have been confirmed and extended by another study,^26^ which used mouse hepatocytes. Unlike classic mitochondrial membrane uncouplers such as 2,4-dinitrophenol, usnic acid stimulates the production of reactive oxygen species as well as depletes ATP levels.^26^ The resulting lipid peroxidation and oxidative damage causes cytotoxicity and cell death. Thus, the hepatotoxicity observed in humans consuming relatively high doses of (+)-usnic acid described below may be a direct result of the oxidative damage component of (+)-usnic acid’s hepatotoxicity rather than its membrane uncoupling activity.

### Humans

Lichens that contain (+/−)-usnic acid, including Usnea species, have been reported to cause contact dermatitis. It is particularly prevalent in Scandinavia where it is called lichen picker’s dermatitis and can be caused by other lichen secondary metabolites such as atranorin and evernic acid in addition to (+/−)-usnic acid.^63-66^

Hepatotoxicity associated with ingestion of high doses of (+)-usnic acid has a greater implication for potential human toxicity of Usnea lichens, however. In 2000, Favreau et al.^67^ reported that seven previously healthy patients developed acute hepatitis after ingesting LipoKinetix (Syntrax, Cape Girardeau, MO) and recovered spontaneously after discontinuing its use. Subsequently, two more cases of acute hepatitis were reported after taking LipoKinetix with one resulting in a liver transplant.^68^ LipoKinetix was a multi-ingredient product; one capsule contained 25 mg of norephedrine hydrochloride, 100 mg of (+)-usnic acid, 100 μg of 3,5-diiodothyronine, 3 mg of yohimbine hydrochloride, and 100 mg of caffeine. It was sold as a dietary supplement to promote weight loss. The manufacturer claimed that LipoKinetix “affects oxidative phosphorylation in such a way that an incredible amount of fatty acids are burned,” therefore promoting weight loss. The recommended dose of LipoKinetix was one or two capsules three times per day, which is 2–5×higher than (+/−)-usnic acid doses used in traditional Chinese medicine. Production and sale of LipoKinetix was terminated in 2001, although Syntrax continued to produce a product with similar ingredients, but without (+)-usnic acid, which was called AdipoKinetix.

UCP-1 (BDC Nutrition, Richmond, KY) was marketed as a weight-loss product containing 150 mg of usnic acid, 525 mg of L-carnitine, and 1,050 mg of calcium pyruvate per capsule. The recommended dose of UCP-1 was three capsules three times per day (1,350 mg/day). Sanchez et al.^69^ reported the development of severe liver failure in two patients who were taking the recommended dose of UCP-1. One resulted in a liver transplant. Durazo et al.^70^ also reported one case of a healthy woman who, after taking pure (+)-usnic acid (Industrial Strength AAA Services, Frazer Park, CA) for weight loss, presented with liver failure requiring a transplant. The recommended dose of pure (+)-usnic acid from this manufacturer was 500 mg/day.

The U.S. Food and Drug Administration (FDA) has received at least 21 adverse event reports including one death attributed to weight-loss dietary supplements containing (+)-usnic acid (LipoKinetix and UCP-1) or pure (+)-usnic acid. In total, 12 cases associated with hepatotoxicity appeared in the literature, and are summarized in Guo et al.^24^ These cases included eight females and four males; the median age of the patients was 31 years old. Two patients required liver transplantation and the others ultimately recovered. While the total number of people who have experimented with weight-loss supplements containing (+)-usnic acid is unknown, the manufacturer of LipoKinetix has claimed to have sold over 30,000 bottles of the supplement.^71^

## Reproductive and Developmental Toxicity

A comprehensive literature search found no studies that evaluated the reproductive and developmental toxicity of Usnea lichens.

## Carcinogenicity

There are no reports of carcinogenic activity for either (+/−)-usnic acid or Usnea lichen preparations.

## Genetic Toxicity

Although extracts of Usnea lichens have not been directly tested for mutagenicity, purified secondary metabolites that are present in Usnea species have been tested in in vitro assays. For example, Shibamoto and Wei^28^ tested the mutagenicity of usnic acid along with two other lichen constituents: physodic (5’-carboxy-3,4’-dihydroxy-5-methyl-caproyl-6’-pentyl-6-carboxy-diphenyl ether-2’,6-lactone) and physodalic acid (3’-acetoxyl-5’-carboxy-3,4’-dihydroxy-2-formyl-5,6’-dimethyl-3’-methylacetoxy-6-carboxy-diphenyl ether-2’,6-lactone) in two Salmonella typhimurium strains (TA98 and TA100) with or without S9 addition. Physodalic acid exhibited a clear dose-related mutagenicity in TA100; the addition of S9 mix increased mutagenicity fourfold at the high dose (400 μg/plate). In contrast, usnic and physodic acids showed no mutagenicity in tested strains including TA98 with or without S9 addition at doses up to 200 μg/plate for both chemicals. Koparal and coworkers^72^ evaluated (+)-usnic acid and (−)-usnic acid genotoxicity in human lymphocytes from two healthy male donors in vitro using the cytokinesis-blocked micronucleus (CBMN) assay. The results obtained from their study suggest that even though the number of micronuclei was higher in both usnic acid enantiomers-treated human lymphocytes in comparison to those in the control, the induction was not significant statistically. The authors concluded that both (+)-usnic acid and (−)-usnic acid were nongenotoxic as shown by the absence of micronucleus induction in human lymphocytes. Oral administration of a single dose of either 100 or 200 mg/kg (+)-usnic acid caused a slight increase in micronucleated erythrocytes in the mice 24 and 48 hours after treatment, which did not reach statistical significance and returned to control levels by 72 hours.^73^

## Study Rationale

Informed by the adverse events described above that were first reported by Medwatch in November 2001,^30^ the Center for Food Safety and Applied Nutrition (CFSAN) of the FDA issued a warning letter,^74^ on November 19, 2001, entitled “FDA Warns Consumers Not to Use the Dietary Supplement LipoKinetix,” because it had been implicated in a number of serious liver injuries. After receiving additional reports of persons who developed liver injury or liver failure while using LipoKinetix, FDA subsequently issued a strong recommendation to the manufacturer, Syntrax Innovation Inc., to withdraw the product from the market (Letter to Distributor on Hazardous Dietary Supplement LipoKinetix).^75^ However, botanical extracts of Usnea lichen species which contain (+)-usnic acid are still marketed as herbal antimicrobials.

To further understand the risk to human health of usnic acid and Usnea preparations, the Office of Dietary Supplement Programs of CFSAN nominated Usnea lichen preparations (U. barbata) to NTP for the evaluation of short-term and long-term toxicity, in January 2005 (see Frankos^30^). The study documented in this report is a 3-month subchronic study of Usnea lichen extract, administered in feed to B6C3F1/Nctr mice and F344/N Nctr rats. The doses of Usnea lichen preparation used in this study were based on their (+/−)-usnic acid concentrations and matched those of a companion study of pure (+)-usnic acid, which is reported on in NTP TOX 104.^76^ A 14-day range-finding study of the Usnea lichen preparation (Appendix J) was conducted prior to this 3-month study to confirm that the rats and mice could tolerate exposure to the proposed doses.