# Appendix K Toxicokinetic Studies

## K.1 Background

Toxicokinetic studies were performed to complement the 2-week range-finding feed studies and were primarily designed to establish the steady-state concentrations of usnic acid in the liver of F344/N Nctr rats and B6C3F1/Nctr mice following a 2-week exposure to either (+)-usnic acid or Usnea lichens in feed. The data were required to compare the in vitro and in vivo hepatotoxicity of usnic acid. The studies therefore utilized individual animals for each time point rather than taking serial blood samples so that liver and other tissues could be collected. This method also had the advantage that the animal’s feeding behavior was not disrupted as would have occurred if serial blood samples had been collected.

## K.2 Materials and Methods

Eight-week-old F344/N Nctr rats and B6C3F1/Nctr mice were fed either (+)-usnic acid or Usnea lichens in feed, as was used for the 2-week range-finding studies (Appendix J of this report and Appendix J of NTP TOX 104^76^). Exposure groups and sacrifice time points for the rats and mice are listed in Table K-1 and Table K-2, respectively. A major objective of this study was to provide data on hepatic concentrations of (+/−)-usnic acid following exposure in feed throughout the daily feeding cycle, which required animals to be euthanized for each time point. Because of the large number of animals required and the lack of significant sex differences in observed effects on body weight and survival (Appendix J), only one sex from each species was evaluated (i.e., female rats and male mice). Feed (powdered NIH-41) and water were provided ad libitum. The animals were housed one per cage and kept on a 12-hour light and dark cycle, but each experimental group was divided between different animal rooms on light cycles that were 11 hours out of phase so that the required circadian sacrifices could be conducted within normal work hours. The animals were serially sacrificed by decapitation on the 13th day of exposure, at 4-hour intervals starting at 1 hour after lights off (HALO). Liver and serum were collected from the sacrificed animals and stored at −80°C until analysis.

Two methods were used to determine hepatic usnic acid concentrations. Method 1 was a macro method, which incorporated an enzyme hydrolysis stage to determine whether conjugated usnic acid was present in the tissue. It was used to analyze the rat liver samples and the initial analysis of mouse liver. Subsequently, Method 2, which incorporated an internal standard, required less tissue and allowed higher throughput, was developed to complete the analysis of mouse liver and to evaluate both rat and mouse serum. Both methods gave similar values when individual liver samples were compared. Neither method resolved (−)-usnic acid from (+)-usnic acid, therefore, the detected usnic acid is referred to as (+/−)-usnic acid. However, when chiral column separation was used to resolve the usnic acid enantiomers in samples of the Usnea lichen preparations used in this study, the relative concentrations were 97.5% ± 0.2% (+)-usnic acid and 2.5% ± 0.2% (−)-usnic acid (Appendix H). Because inter-conversion of the enantiomers is not expected to occur in vivo, it was therefore assumed that the (+/−)-usnic acid present in tissue samples from animals exposed to (+)-usnic acid was essentially 100% (+)-usnic acid, and that present in tissue samples from animals exposed to Usnea lichen was essentially >97% (+)-usnic acid.

### K.2.1 Method 1

Liver samples (0.5–1.0 g) were homogenized in sufficient homogenization buffer (0.2 M sodium phosphate dibasic [Sigma-Aldrich, trihydrate] adjusted to pH 4.6 with formic acid) to produce a 10% (w/v) homogenate, using an Ultra-Torrax homogenizer followed by ultra-sonication with a Vibra-Cell sonicator at 100 kJ (5–10 seconds). Helix pomata β-glucuronidase (Sigma-Aldrich, H-5, 400 units/mg) was reconstituted with 0.02 M ammonium acetate buffer to make a stock enzyme solution containing 40,000 units/mL. Aliquots of β-glucuronidase solution were added to 1 mL aliquots of liver homogenate to produce final β-glucuronidase concentrations of 4,000 to 24,000 units/mL and were incubated in a water bath at 39°C for 20 hours. For nonhydrolysed controls, equal volumes of acetate buffer were substituted for the β-glucuronidase solution. After incubation the samples were extracted with 3 × 3 mL of ethyl acetate and the combined extracts evaporated under nitrogen at 40°C. The residue was reconstituted with 2 mL of acetonitrile:ethyl acetate (75:25) acidified with 0.6% formic acid. The residue solutions were filtered through 0.45 µm nylon syringe filters into amber HPLC vials.

Samples were analyzed using a Waters HPLC-PDA system, which included a Model 600E controller, 717plus autoinjector, and a 996-photodiode array detector. Injections (35 µL) were passed through a 250 × 4.60 mm (4 µm particle) Phenomenex Prodigy 5 μm ODS-3 100 Å column maintained at 35°C. Mobile phase consisted of 73% acetonitrile in 0.05% formic acid in water. The flow rate was held at 1.1 mL/minute for 30 minutes and usnic acid peaks were detected at 232 nm. Recovery of (+)-usnic acid was 100% with or without enzyme from spiked control tissue.

### K.2.2 Method 2

This method utilized dexamethasone as an internal standard and a Waters Acquity HPLC system. Weighed samples of frozen liver, weighing approximately 50 mg, were homogenized in 950 µL of homogenization buffer (0.2 M sodium phosphate brought to pH 4.6 with formic acid) using a Vibra-Cell sonicator at 100 kJ (5–10 seconds). Internal standard (30 pmol of dexamethasone-21-acetate (Sigma-Aldrich) in 30 µL of acetonitrile) was added to each sonicate, followed by a further 5-second sonication. Three 300 µL aliquots of the resulting sonicates were extracted three times with 1 mL of ethyl acetate and the pooled ethyl acetate extracts from each aliquot were evaporated to dryness under nitrogen at 40°C. The dried sample extracts were resuspended in 200 µL Mobile Phase A/B, 20/80 (see below) and filtered through 0.22 µm polyvinylidene difluoride (PVDF) filters (Ultrafree centrifugal filters, Millipore Inc., Billerica, MA). For each sample replicate, 40 µL of filtrate was mixed with 40 µL Mobile Phase A (see below) in an UPLC sample vial and the resulting mixture analyzed.

The UPLC system consisted of an Acquity sample manager, a solvent manager and photodiode array modules (Waters Inc., Milford, MA) and utilized an Acquity BEH C18, 1.7 µm, 2.1 × 50 mm UPLC column in conjunction with a BEH C18, 1.7 µm, 2.1 × 5 mm Acquity Vanguard precolumn. Mobile Phase A was water/acetonitrile/acetic acid (94.5/5.0/0.5, v/v/v) and Mobile Phase B was acetonitrile/acetic acid (99.5/0.5, v/v) and the (+/−)-usnic acid and dexamethasone-21-acetate peaks were resolved with a binary linear gradient of 40% B to 100% B between 1 and 4 minutes of a 10-minute sample cycle time with a flow rate of 0.25 mL/min. The sample runs were returned to initial conditions at 7 minutes. The column was maintained at ambient temperature and sample injection volume was 5 µL. The peaks were monitored at 258 nm. Sample recovery was calculated using standards wherein 10 pmol of dexamethasone-21-acetate were added directly to the UPLC sample vial and (+)-usnic acid standard curves were constructed for each sample batch by adding known concentrations of (+)-usnic acid to homogenates of liver from untreated rats or mice to give a concentration range equivalent to 20–300 µM in liver.

### K.2.3 Assay of (+/−)-Usnic Acid in Serum

For rat samples, 25 µL of thawed serum was mixed with 10 pmol of dexamethasone-12-acetate in 10 µL acetonitrile, 3.5 µL of 1 M sodium acetate (adjusted to pH 5.0 with acetic acid) and 500 µL of acetonitrile. The mixtures were sonicated for 5 minutes in a sonicator bath, and then centrifuged at 1,200 g for 5 minutes. Mouse serum samples were processed in the same way, except 12.5 µL of sample serum and 12.5 µL of commercial mouse serum were used due to the limited volumes of mouse sample serum that were available. After centrifugation, a 400 µL aliquot of each supernatant was evaporated to dryness in a centrifugal vacuum evaporator (Savant SpeedVac, Thermo Scientific.com). The dried sample extracts were resuspended in 100 µL Mobile Phase A/B, 20/80 (see Method 2) and filtered through 0.22 µm PVDF filters. For each sample replicate, 40 µL of filtrate was mixed with 40 µL Mobile Phase A (see Method 2) in a UPLC sample vial and the resulting mixture analyzed by the UPLC method that was used for liver samples (see Method 2). The (+)-usnic acid standard curves were constructed for each sample batch by adding known concentrations of (+)-usnic acid to serum obtained from untreated rats or mice (Innovative Research Inc., Novi, MI) to give a concentration range equivalent to 20–300 µM in sample serum.

## K.3 Results

### K.3.1 Rat Liver

Hepatic concentrations of (+/−)-usnic acid in female F344/N Nctr rats exposed to either 360 or 1,250 ppm (+)-usnic acid or ground Usnea lichens at a equivalent to 360 ppm (+/−)-usnic acid are shown in Figure K-1. For each exposure, (+/−)-usnic acid concentrations appeared to have reached a steady-state and did not significantly vary with the circadian time point at which the animal was sacrificed. Increasing the (+)-usnic acid exposure 3.5-fold from 360 to 1,250 ppm only increased hepatic concentrations of (+/−)-usnic acid from approximately 75–80 nmol/g wet weight (µM cellular concentration) to approximately 90–95 nmol/g wet weight (µM). Interestingly, hepatic concentrations of (+/−)-usnic acid in rats exposed to feed containing Usnea lichens at a concentration that provided 360 ppm of (+/−)-usnic acid, exceeded that of both the 360 and 1,250 ppm (+)-usnic acid groups. Hydrolysis of liver homogenates with β-glucuronidase did not increase hepatic (+/−)-usnic acid concentrations, which suggested that only negligible amounts of usnic acid were glucuronidated. The actual mean daily doses of pure (+)-usnic acid or (+/−)-usnic acid in Usnea lichens were calculated from observed feed consumption and body weight data and are compared with the target doses in Table K-3. Actual doses were slightly higher than target for both the rats and mice.

### K.3.2 Rat Serum

Serum concentrations of (+/−)-usnic acid in female F344/N Nctr rats exposed to either 360 or 1,250 ppm (+)-usnic acid or ground Usnea lichens equivalent to 360 ppm (+/−)-usnic acid are shown in Figure K-2. While mean serum (+/−)-usnic acid concentrations were similar to hepatic concentrations for the 360 ppm (+)-usnic acid and 360 ppm Usnea lichens exposed groups, serum concentrations were greater and more variable than hepatic concentrations for the 1,250 ppm exposed group and ranged between 170 and 240 µM at different timepoints.

### K.3.3 Mouse Liver

Hepatic concentrations of (+/−)-usnic acid in male B6C3F1/Nctr mice exposed to either 180 or 600 ppm (+)-usnic acid or ground Usnea lichens equivalent to 180 ppm (+/−)-usnic acid are shown in Figure K-3. For each exposure, (+/−)-usnic acid concentrations appeared to have reached a steady state and did not significantly vary with the circadian time point at which the animal was sacrificed. In contrast to rats, the hepatic concentrations of (+/−)-usnic acid in both the 180 ppm (+)-usnic acid and the 180 ppm Usnea lichens exposed groups in mice were similar and ranged between 38 and 58 nmol/g wet weight (µM cellular concentration). The hepatic concentration of (+/−)-usnic acid in the 600 ppm (+)-usnic acid was greater and ranged between 85 and 115 nmol/g wet weight (µM). Hydrolysis of liver homogenates with β-glucuronidase did not increase hepatic (+/−)-usnic acid concentrations, which suggested that only negligible amounts of usnic acid were glucuronidated.

### K.3.4 Mouse Serum

Serum concentrations of (+/−)-usnic acid in male B6C3F1/Nctr mice exposed to either 180 or 600 ppm (+)-usnic acid or ground Usnea lichens equivalent to 180 ppm (+/−)-usnic acid are shown in Figure K-4. Serum (+/−)-usnic acid concentrations were greater than hepatic concentrations for the 180 and 600 ppm (+)-usnic acid-exposed groups; and serum concentrations were greater than hepatic concentrations for the 180 ppm Usnea lichens exposed group, which ranged between 60 and 100 µM.

## K.4 Discussion

The study utilized exposures of 360 and 180 ppm (+)-usnic acid for F344/N Nctr rats and B6C3F1/Nctr mice respectively, which resulted in hepatic and serum (+/−)-usnic acid concentrations that appeared to have reached steady-state levels that ranged between 40 and 100 μM. These exposures, which were designed to deliver 30 mg (+)-usnic acid per kg/day, did not produce hepatotoxicity in the 2-week exposure studies (Appendix J). The study also utilized exposures of 1,250 and 600 ppm (+)-usnic acid for F344/N Nctr rats and B6C3F1/Nctr mice, respectively, which resulted in hepatic and serum (+/−)-usnic acid concentrations that appeared to have reached steady-state levels that ranged between 85 and 115 µM in liver and 150 and 250 µM in serum. These exposures, which were designed to deliver 100 mg (+)-usnic acid per kg/day, did produce hepatotoxicity in some cases in the 2-week exposure studies. Exposure of isolated rodent hepatocytes to (+)-usnic in vitro has been reported to result in adenosine 5’-triphosphate depletion and complete cytotoxicity after 24 hours at doses >2 µM.^24,26^ Taken together, the observations suggest that (+)-usnic acid is much less toxic to hepatocytes in vivo than in vitro.

Exposure to (+)-usnic acid in ground Usnea lichens resulted in greater (+/−)-usnic acid concentrations in rat liver and serum and in mouse serum than from exposure to equivalent concentrations of pure (+)-usnic acid. This observation was particularly evident in rat liver wherein exposure to 360 ppm (+/−)-usnic acid as Usnea lichens resulted in greater concentrations than did exposure to 1,250 ppm of pure (+)-usnic acid, which suggests that additional components in the ground lichens reduce the hepatic clearance of (+/−)-usnic acid. Feed consumption was similar across the three exposed groups.

Table K-1 Toxicokinetics Study of (+)-Usnic Acid in Rats

Group | Exposure^a^ (ppm in Feed) | Sample Time^b^ (HALO) | Number of Rats^c^ (Female)
1 | 360 (+)-usnic acid | 1 | 4
2 | 360 (+)-usnic acid | 5 | 4
3 | 360 (+)-usnic acid | 9 | 4
4 | 360 (+)-usnic acid | 13 | 4
5 | 360 (+)-usnic acid | 17 | 4
6 | 360 (+)-usnic acid | 21 | 4
7 | 360 Usnea lichens^d^ | 1 | 4
8 | 360 Usnea lichens | 5 | 4
9 | 360 Usnea lichens | 9 | 4
10 | 360 Usnea lichens | 13 | 4
11 | 360 Usnea lichens | 17 | 4
12 | 360 Usnea lichens | 21 | 4
13 | 1,250 (+)-usnic acid | 1 | 4
14 | 1,250 (+)-usnic acid | 5 | 4
15 | 1,250 (+)-usnic acid | 9 | 4
16 | 1,250 (+)-usnic acid | 13 | 4
17 | 1,250 (+)-usnic acid | 17 | 4
18 | 1,250 (+)-usnic acid | 21 | 4
Totals | | | 72

^a^ The rats were exposed via the feed as with the 2-week studies. Exposure levels were selected from the 2-week study data.

^b^ The animals were sacrificed at 4-hour intervals starting 1 HALO (hours after lights on) on the 13th day of exposure.

^c^ Only females were evaluated because significant sex differences were not observed in the 2-week study.

^d^ Usnea lichens was added to feed to provide the listed concentration of (+/−)-usnic acid.

Table K-2 Toxicokinetics Study of (+)-Usnic Acid in Mice

Group | Exposure^a^ (ppm in Feed) | Sample Time^b^ (HALO) | Number of Mice^c^ (Male)
1 | 180 (+)-usnic acid | 1 | 4
2 | 180 (+)-usnic acid | 5 | 4
3 | 180 (+)-usnic acid | 9 | 4
4 | 180 (+)-usnic acid | 13 | 4
5 | 180 (+)-usnic acid | 17 | 4
6 | 180 (+)-usnic acid | 21 | 4
7 | 180 Usnea lichens^d^ | 1 | 4
8 | 180 Usnea lichens | 5 | 4
9 | 180 Usnea lichens | 9 | 4
10 | 180 Usnea lichens | 13 | 4
11 | 180 Usnea lichens | 17 | 4
12 | 180 Usnea lichens | 21 | 4
13 | 600 (+)-usnic acid | 1 | 4
14 | 600 (+)-usnic acid | 5 | 4
15 | 600 (+)-usnic acid | 9 | 4
16 | 600 (+)-usnic acid | 13 | 4
17 | 600 (+)-usnic acid | 17 | 4
18 | 600 (+)-usnic acid | 21 | 4
Totals | | | 72

^a^ The mice were exposed via the feed as with the 2-week studies. Exposure levels were selected from the 2-week study data.

^b^ The animals were sacrificed at 4-hour intervals starting 1 HALO (hours after lights on) on the 13th day of exposure.

^c^ Only males were evaluated because significant sex differences were not observed in the 2-week study.

^d^ Usnea lichens was added to feed to provide the listed concentration of (+/−)-usnic acid.

Table K-3 Comparison of Observed Actual Doses to Target Doses for the Toxicokinetics Study of Usnea Lichens

| Target Dose^a^ (mg/kg/day) | Actual Dose Week 1^b^ (mg/kg/day) | Actual Dose Week 2^b^ (mg/kg/day) | Average for 14 Days (mg/kg/day)
Female Rats
(+)-Usnic Acid 360 ppm | 30 | 40.9 | 44.2 | 42.6
(+)-Usnic Acid 1,250 ppm | 100 | 107.3 | 124.3 | 115.8
(+/−)-Usnic Acid 360 ppm^c^ | 30 | 39.0 | 43.1 | 41.1
Male Mice
(+)-Usnic Acid 180 ppm | 30 | 35.1 | 36.9 | 36.0
(+)-Usnic Acid 600 ppm | 100 | 119.6 | 135.2 | 127.4
(+/−)-Usnic Acid 180 ppm^d^ | 30 | 36.6 | 36.8 | 36.7

^a^ Calculated from historical body weight and feed consumption data.

^b^ Calculated from observed body weight and feed consumption data.

^c^ Given as Usnea lichens powder standardized to 360 ppm (+/−)-usnic acid.

^d^ Given as Usnea lichens powder standardized to 180 ppm (+/−)-usnic acid.

Figure K-1

Concentrations of (+/−)-Usnic Acid in Livers from Female Rats Exposed to Either (+)-Usnic Acid or Ground Usnea Lichens in Feed

Figure K-2

Serum Concentrations of (+/−)-Usnic Acid in Female Rats Exposed to Either (+)-Usnic Acid or Ground Usnea Lichens in Feed

Figure K-3

Concentrations of (+/−)-Usnic Acid in Livers from Male Mice Exposed to Either (+)-Usnic Acid or Ground Usnea Lichens in Feed

Figure K-4

Serum Concentrations of (+/−)-Usnic Acid in Male Mice Exposed to Either (+)-Usnic Acid or Ground Usnea Lichens in Feed