# Appendix J Acute Toxicity

## J.1 Background

Acute toxicity (range-finding) studies, consisting of 2-week feed studies, were conducted as part of a National Center for Toxicological Research (NCTR) experimental study to investigate the acute toxicity of both (+)-usnic acid and Usnea lichens. This summary report focuses on the acute toxicity of Usnea lichens.

## J.2 Experimental Methods

Animals: F344/N Nctr rats and B6C3F1/Nctr mice were provided by the NCTR breeding colonies and allocated to the experiment at 3 weeks of age. The experimental loading was staggered so that the animals were loaded in three replicates of either one or two per exposure group at weekly intervals. Loading of mice preceded loading of rats. The animals were loaded on the Multigeneration Support System (MGSS) and assigned to exposure groups at 6 weeks of age. The NCTR biometry staff provided a rack configuration and exposure randomization documents to control bias. Exposure, via feed, commenced at 8 weeks of age and proceeded for 14 days. Lichen in feed was standardized to (+)-usnic acid content (Table J-1, Table J-2). The initial range-finding study design was adapted when mice in both the 1,200 ppm and 600 ppm groups died or became moribund within the first few days of dosing. Because of Institutional Animal Care and Use Committee (IACUC) concerns, no additional mice were loaded into the 1,200 ppm group in subsequent replicates but were instead exposed to 10 ppm (+/−)-usnic acid. The initially proposed 2,500 ppm group was also removed and a 20 ppm group added in the rat study. The animal numbers in each exposure group are shown in Table J-1 and Table J-2 for rats and mice, respectively. The animals were weighed weekly prior to exposure, and then twice weekly (i.e., every 3 or 4 days) during the dosing period so that any exposure-related changes in body weight could be closely monitored. Dosed feed was allocated weekly in weighed amounts, weighed twice weekly, and the feed remaining measured so that daily feed consumption could be monitored.

The animals were sacrificed by decapitation and trunk blood was collected. Tissues were examined for gross abnormalities and observed lesions were processed for histopathological evaluation. These examinations were conducted under the supervision of the study pathologist. Gross examination data were recorded. The liver, kidneys, heart, and lungs from all animals were weighed wet as soon as possible after dissection.

All protocol-specified tissues were examined grossly, removed, and preserved in 10% neutral buffered formalin except the eyes and testes, which were preserved in modified Davidson's fixative. The protocol-required tissues including all gross lesions were trimmed, processed, and embedded in Formula R^®^, sectioned at approximately 5 µm, and stained with hematoxylin and eosin. Tissues were examined microscopically and, when applicable, nonneoplastic lesions were graded for severity as 1 (minimal), 2 (mild), 3 (moderate), or 4 (marked).

Test article: Usnea lichens were obtained from Mountain Rose Herbs (Eugene, OR; lot 2074 received September 12, 2006; 9.07 kg was received in this shipment) and characterized by microscopic evaluation to consist predominantly of U. scabrata and U. cavernosa. Ground lichens were prepared from these species by hand grinding under liquid nitrogen and sieving the ground product consecutively through 20-, 40-, and 60-gauge sieves on a mechanical shaker. The sieved content was blended and evaluated for (+/−)-usnic acid content, which was established as 2.63 ± 0.11% dry weight. The ground Usnea lichens were blended into powdered NIH-41 autoclaved rodent diet to achieve the required (+/−)-usnic acid concentrations based on this concentration. Analysis of feed consignments established that in all batches of dosed feed, the (+/−)-usnic acid concentration was within 6% of the target concentration.

## J.3 Results

Body weight: Exposure of male and female F344/N Nctr rats to Usnea lichens at 1,250 ppm (+/−)-usnic acid decreased the body weights of both sexes (Figure J-1). Mean body weight was reduced by 16.5% and 40.3% after 3 and 10 days of exposure, respectively, for male rats and by 12.8% and 34.5% after 3 and 10 days of exposure, respectively, for females. The lower exposure concentrations of Usnea lichens had little or no effect on the body weights of either sex, with mean values being only slightly lower for the 360 ppm (+/−)-usnic acid-exposed females than for the corresponding values of the control groups.

Large decreases in body weight were observed in both male and female B6C3F1/Nctr mice exposed to Usnea lichens providing doses of 600 and 1,200 ppm (+/−)-usnic acid after 3 days of exposure (Figure J-2). The decrease was less severe between days 3 and 14 of exposure for the surviving male mice in the 600 ppm group. Mice in the lower exposed groups either maintained their weight or increased it slightly during the 14 days of exposure.

Survival: In male and female F344/N Nctr rats, exposure to Usnea lichens providing 1,250 ppm (target dose 100 mg/kg/day) of (+/−)-usnic acid induced morbidity so that all animals in the group were removed from the study by the 11th and 10th day of exposure for males and females, respectively (Figure J-3). The rats in the other exposed groups all survived until the end of the study.

In male and female B6C3F1/Nctr mice, exposure to Usnea lichens providing 1,200 ppm (target dose 200 mg/kg/day) of (+/−)-usnic acid induced early death or morbidity so that all animals assigned to the group were removed from the study by the 4th day of exposure (Figure J-4). This exposure was discontinued after the first replicate of two mice per sex. Exposure to 600 ppm (100 mg/kg/day) also caused death or morbidity during the first few days of exposure. All female mice had been removed from the study by the 4th day, whereas two of the five male mice survived the duration of exposure. The mice in the other dosed groups all survived until the end of the study.

Histopathological effects of 2-week exposure to Usnea lichens: The histopathological effects of 2-week exposure to Usnea lichens containing (+/−)-usnic acid in feed are described below and in Table J-3and Table J-4. Histopathological lesions suggestive of liver toxicity were observed in all male and female F344/N Nctr rats exposed to 1,250 ppm (+/−)-usnic acid as Usnea lichens (Table J-3), despite these animals being removed early due to morbidity. Thymic atrophy was also observed in male and female rats in this group and seminal vesicle atrophy was observed in the males. These lesions are characteristic of a toxic stress response. No exposure-related lesions were detected in groups exposed at lower concentrations. In B6C3F1/Nctr mice, (Table J-4) exposure to Usnea lichens resulted in hepatotoxic lesions in 100% of male and 40% of female mice in the 600 ppm group and 40% of male mice in the 180 ppm group. Thymic atrophy was observed in 20% of female and 80% of male mice in the 600 ppm group. No other exposure-related lesions were observed at these or lower exposures. The two male and two female mice exposed to 1,200 ppm (+/−)-usnic acid in Usnea lichens all exhibited thymic atrophy, but none exhibited hepatocellular lesions. This observation suggests that liver toxicity is not the major cause of death and morbidity in these animals.

Hepatocellular alteration in this 2-week range-finding study included a variety of changes associated with hepatocellular toxicity. In both species, the affected animals displayed one or more of the following changes: cell swelling as well as cell contraction, cytoplasmic vacuolization or clearing, clumping (increased densities) of organelles, and, in many animals, an increased cytoplasmic eosinophilia. Nuclear chromatin clumping with early karyorrhexis was occasionally observed; less frequently noted were single necrotic cells characterized by their dark appearance and by being dislodged from their normal position. These changes represent patterns of cell degeneration with differences depending on the dose of toxin and the state of metabolism in the cell at the time of injury. The lesions described are part of a cascade of factors leading to irreversible degeneration and eventually necrosis.

Atrophy characterized by a decrease in the organ size was noted involving the thymus and seminal vesicles and was probably associated with decreased caloric intake (feed avoidance) and stress-associated metabolic changes. All other lesions were considered spontaneous background changes.

## J.4 Adenosine 5’-Triphosphate Concentrations in Liver

Usnic acid is a known mitochondrial uncoupler and has been reported to decrease adenosine 5’-triphosphate (ATP) levels in cultured hepatocytes.^26^ As part of the 2-week range-finding study, ATP concentrations were evaluated in liver samples from both rats and mice exposed to Usnea lichens, containing (+/−)-usnic acid for 14 days.

### J.4.1 Methods

Hepatic ATP concentrations were determined using ATP Bioluminescent Assay kits (Sigma-Aldrich, St. Louis, MO, #FL-AA) on a Veritas 9100 Microplate Luminometer (Turner BioSystems, Sunnydale, CA). Liver extract (5%) was prepared in 2.5% trichloroacetic acid (TCA) and neutralized with 0.1 M Tris-Acetate buffer (pH 7.75) before using in a microtiter plate for ATP estimation. The luminescence data were converted to μmoles of ATP from standard solutions run with each assay plate. SAS (version 9.2, TS level 1M0) was used to produce means, standard error values and significant differences between exposure groups via a Dunnett test evaluation and a linear trend test run under the SAS General Linear Models program.

### J.4.2 Results

As shown in Table J-5, ATP concentrations in livers from both male and female F344/N Nctr rats were decreased by 2-week exposure to (+/−)-usnic acid in Usnea lichens. The decreases were greatest in the rats from the 1,250 ppm groups, which were removed early due to morbidity (Table J-5). In males, ATP concentrations were significantly decreased in the 60 ppm and higher exposed groups, whereas in females, ATP concentrations were significantly decreased only in the 360 and 1,250 ppm groups. As shown in Table J-6, ATP concentrations were decreased by a smaller amount in livers from male and female B6C3F1/Nctr mice than in rat liver. Statistically significant decreases were observed in the male 600 and 1,200 ppm groups but were not observed in the female 600 ppm group.

## J.5 Serum Parameters in F344/N Nctr Rats Exposed to Usnea Lichens Containing (+/−)-Usnic Acid

As part of these 2-week range-finding toxicity studies, serum triglyceride and cholesterol concentrations and alanine aminotransferase (ALT) activity were evaluated in trunk blood samples from both male and female F344/N Nctr rats that were sacrificed following 14 days of exposure or were removed from the study due to morbidity.

As shown in Table J-7, exposure to Usnea lichens containing 1,250 ppm (+/−)-usnic acid caused a significant increase in serum ALT values in female rats but not in male rats, despite hepatocellular toxicity being observed in both sexes. Serum triglyceride concentrations were significantly decreased in both male and female F344/N Nctr rats exposed to the 1,250 ppm group but not at lower exposures, whereas serum cholesterol concentrations were significantly decreased only in the 1,250 ppm females.

Table J-1 Two-week Range-finding Study for Usnea Lichens in Rats

Exposure^a^ | Target Dose^b^ | Males^c^ | Females^c^
None | 0 | 5 | 5
20 | 2 | 5 | 5
60 | 5 | 5 | 5
120 | 10 | 5 | 5
360 | 30 | 5 | 5
1,250 | 100 | 5 | 5
Totals | | 30 | 30

^a^ Ground Usnea lichens was added to feed to produce the desired concentration (ppm) of (+/−)-usnic acid. The animals received dosed feed for 14 days prior to sacrifice.

^b^ Approximate target dose in mg/kg/day calculated from NCTR historical body weight and feed consumption data.

^c^ Number of animals used.

Table J-2 Two-week Range-finding Study for Usnea Lichens in Mice

Exposure^a^ | Target Dose^b^ | Males^c^ | Females^c^
None | 0 | 5 | 5
30 | 5 | 5 | 5
60 | 10 | 5 | 5
180 | 30 | 5 | 5
600 | 100 | 5 | 5
1,200 | 200 | 2 | 2
10^d^ | 2 | 3 | 3
Totals | | 30 | 30

^a^ Ground Usnea lichens was added to feed to produce the desired concentration (ppm) of (+/−)-usnic acid. The animals received dosed feed for 14 days prior to sacrifice.

^b^ Approximate target dose in mg/kg/day calculated from NCTR historical body weight and feed consumption data.

^c^ Number of animals used.

^d^ Because the mice in the first replicate exposed to 1,200 and 600 ppm (+/−)-usnic acid in Usnea lichens died or became morbid during the first 4 days of exposure, the 1,200 ppm group was discontinued and replaced with a 10 ppm exposure group. However, these animals were not evaluated because no effects were noted in the animals in the 30 ppm groups.

Table J-3 Incidence of Nonneoplastic Lesions in Rats in the Two-week Study of Usnea Lichens^a^

| 0 ppm | 20 ppm | 60 ppm | 120 ppm | 360 ppm | 1,250 ppm
Males
Liver, Cellular Alteration | 0 | 0 | 0 | 0 | 0 | 100
Thymus Atrophy | 0 | 0 | 0 | 0 | 0 | 100
Seminal Vesicle Atrophy | 0 | 0 | 0 | 0 | 0 | 100
Females
Liver, Cellular Alteration | 0 | 0 | 0 | 0 | 0 | 100
Thymus Atrophy | 0 | 0 | 0 | 0 | 0 | 40

^a^ Incidence (%) based on animals per group.

Table J-4 Incidence of Nonneoplastic Lesions in Mice in the Two-week Study of Usnea Lichens^a^

| 0 ppm | 30 ppm | 60 ppm | 180 ppm | 600 ppm | 1,200 ppm
Males
Liver, Cellular Alteration | 0 | 0 | 0 | 40 | 100 | 0
Thymus Atrophy | 0 | 0 | 0 | 0 | 80 | 100
Females
Liver, Cellular Alteration | 0 | 0 | 0 | 0 | 40 | 0
Thymus Atrophy | 0 | 0 | 0 | 0 | 20 | 100

^a^ Incidence (%) based on animals per group.

Table J-5 Hepatic Adenosine 5’-Triphosphate Concentrations in Rats Exposed to Usnea Lichens for Two Weeks^a^

| 0 ppm | 20 ppm (2)^b^ | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 1,250 ppm (100)
Male
Observed Dose^c^ | 0 | 1.5 | 4.3 | 8.8 | 29.1 | 106.5
ATP (µmol/g) | 1.60 ± 0.10 (5)^d^ p ≤ 0.001^e^ | ND | 1.24 ± 0.09 (5) p = 0.044 | 1.21 ± 0.14 (5) p = 0.029 | 0.79 ± 0.10 (5) p ≤ 0.001 | 0.76 ± 0.08 (5) p ≤ 0.001
Female
Observed Dose | 0 | 1.5 | 4.6 | 9.3 | 28.4 | 115.7
ATP (µmol/g) | 1.05 ± 0.06 (5) p ≤ 0.001 | ND | 0.94 ± 0.05 (3) p = 0.221 | 0.97 ± 0.03 (3) p = 0.350 | 0.76 ± 0.08 (3) p = 0.003 | 0.41 ± 0.03 (5) p ≤ 0.001

ATP = adenosine 5’-triphosphate; ND = not determined; liver samples from the rats were not available for assay due to problems with freezer storage.

^a^ Livers from terminal sacrifice and moribund animals were evaluated. Livers from dead animals were not evaluated. Values are expressed as mean ± standard error with sample number in parentheses.

^b^ Target dose in mg/kg/day.

^c^ Actual dose calculated from observed body weight and feed consumption data.

^d^ Number of samples examined shown in parentheses.

^e^ Significance given with the control group is the dose trend; that given with other dose groups is the difference from the control group on a one-tailed Dunnett test.

Table J-6 Hepatic Adenosine 5’-Triphosphate Concentrations in Mice Exposed to Usnea Lichens for Two Weeks^a^

| 0 ppm | 30 ppm (5)^b^ | 60 ppm (10) | 180 ppm (30) | 600 ppm (100) | 1,200 ppm (200)
Male
Observed Dose^c^ | 0 | 4.8 | 10.6 | 31.9 | 101 | 115
ATP (µmol/g) | 1.50 ± 0.23 (5)^d^ p = 0.024^e^ | 1.19 ± 0.04 (5) p = 0.282 | 1.20 ± 0.18 (5) p = 0.295 | 1.11 ± 0.09 (5) p = 0.160 | 0.85 ± 0.33 (4) p = 0.020 | 0.71 ± 0.39 (2) p = 0.025
Female
Observed Dose | 0 | 5.7 | 10.9 | 37.6 | 144 | 234
ATP (µmol/g) | 1.14 ± 0.07 (5) p = 0.051 | 0.96 ± 0.12 (5) p = 0.831 | 0.84 ± 0.13 (5) p = 0.264 | 0.87 ± 0.13 (5) p = 0.311 | 0.70 ± 0.10 (5) p = 0.083 | –^f^

ATP = adenosine 5’-triphosphate.

^a^ Livers from terminal sacrifice and moribund animals were evaluated. Livers from dead animals were not evaluated. Values are expressed as mean ± standard error with sample number in parentheses.

^b^ Target dose in mg/kg/day.

^c^ Actual dose calculated from observed body weight and feed consumption data.

^d^ Number of samples examined shown in parentheses.

^e^ Significance given with the control group is the dose trend; that given with other dose groups is the difference from the control group on a one-tailed Dunnett test.

^f^ All female mice in the 1,200 ppm group were euthanized, moribund, or found dead by study day 4.

Table J-7 Serum Alanine Aminotransferase, Triglyceride, and Cholesterol Concentrations in Rats Exposed to Usnea Lichens for Two Weeks^a^

| 0 ppm | 20 ppm (2.5) | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 1,250 ppm (100)
Male
Alanine Aminotransferase^b^ | 79.4 ± 2.8 (5) p = 0.02^c^ | 75.6 ± 4.3 (5) p = 0.97 | 73.4 ± 1.6 (5) p = 0.99 | 73.2 ± 2.6 (5) p = 0.99 | 85.2 ± 1.8 (5) p = 0.32 | 84.6 ± 5.2 (5) p = 0.37
Triglyceride^d^ | 120 ± 20 (5) p ≤ 0.0001 | 101 ± 14 (5) p = 0.41 | 110 ± 15 (5) p = 0.63 | 101 ± 9 (5) p = 0.40 | 107 ± 11 (5) p = 0.56 | 32.4 ± 2.4 (5) p = 0.0002
Cholesterol^d^ | 80.6 ± 5.0 (5) p = 0.50 | 81.0 ± 4.1 (5) p = 0.85 | 78.6 ± 1.9 (5) p = 0.73 | 80.8 ± 3.8 (5) p = 0.84 | 103 ± 5.8 (5) p = 1.00 | 75.2 ± 6.4 (5) p = 0.51
Female
Alanine Aminotransferase | 73.4 ± 3.0 (5) p = 0.0002 | 72.2 ± 3.0 (5) p = 0.88 | 69.8 ± 2.2 (5) p = 0.94 | 75.0 ± 3.8 (5) p = 0.76 | 73.8 ± 2.9 (5) p = 0.82 | 99.0 ± 11.1 (5) p = 0.005
Triglyceride | 76.2 ± 7.7 (5) p = 0.0003 | 71.4 ± 8.5 (5) p = 0.68 | 76.0 ± 10.0 (5) p = 0.83 | 79.0 ± 9.4 (5) p = 0.90 | 68.0 ± 5.8 (5) p = 0.54 | 37.4 ± 4.3 (5) p = 0.004
Cholesterol | 96.2 ± 2.1 (5) p ≤ 0.0001 | 99.6 ± 3.6 (5) p = 0.96 | 100 ± 1.8 (5) p = 0.97 | 112 ± 4.5 (5) p = 1.0 | 115 ± 2.7 (5) p = 1.0 | 55.4 ± 5.8 (5) p ≤ 0.0001

^a^ Values are expressed as mean ± standard error with sample number in parentheses.

^b^ Activity given as Units/L.

^c^ p values listed under the control group values denote trend test significance, and those beneath the exposed group values denote significance of Dunnett test pairwise comparisons between the feed controls and that exposed group. Two-tailed Dunnett tests were used.

^d^ Concentrations given as mg/dL.

Figure J-1

Effect of Two-week Exposure to Usnea Lichens in Feed on Mean Body Weight in Rats

Figure J-2

Effect of Two-week Exposure to Usnea Lichens in Feed on Mean Body Weight in Mice

Figure J-3

Survival of Rats Exposed to Usnea Lichens in Feed for Two Weeks

Figure J-4

Survival of Mice Exposed to Usnea Lichens in Feed for Two Weeks