# Appendix I Ingredients, Nutrient Composition, and Contaminant Levels in NIH-41 Rodent Diet

Table I-1 Ingredients of NIH-41 Irradiated Diet

Ingredients | Percentage by Weight
Ground Whole Hard Wheat | 34.9
Ground #2 Yellow Corn | 21.0
Ground Whole Oats | 10.0
Wheat Middlings | 10.0
Fish Meal (60% Protein) | 9.0
Soy Oil | 2.0
Soybean Meal (47.5% Protein) | 5.0
Alfalfa Meal (17% Protein) | 2.0
Corn Gluten Meal (60% Protein) | 2.0
Dicalcium Phosphate | 1.5
Brewers Dried Yeast | 1.0
Premixes | 0.5
Ground Limestone | 0.5
Salt | 0.5

Table I-2 Vitamins and Minerals in NIH-41 Irradiated Diet

| Amount | Source
Vitamins
A | 14,500,000 IU | Vitamin A palmitate or acetate
D_3_ | 4,6000,000 IU | D-activated animal sterol
K | 2.8 g | Menadione activity
d-L-Alpha-tocopheryl Acetate | 20,000 IU
Choline | 560 g | Choline chloride
Folic Acid | 2.2 g
Niacin | 30.0 g
d-Pantothenic Acid | 18.0 g | d-Calcium pantothenate
Riboflavin Supplement | 6.6 g
Thiamin | 10 g | Thiamin mononitrate
B_12_ | 58.2 mg
Pyridoxine | 1.7 g | Pyridoxine hydrochloride
Biotin | 113.5 mg | d-Biotin
Minerals
Cobalt | 400 mg | Cobalt carbonate
Copper | 4 g | Copper sulfate
Iron | 60 g | Iron sulfate
Magnesium | 400 g | Magnesium oxide
Manganese | 100 g | Manganese oxide
Zinc | 10 g | Zinc oxide
Iodine | 1,500 mg | Calcium iodate

Table I-3 Results of Analyses for Nutrients and Contaminants in NIH-41 Irradiated Diet^a^

Diet Sample SCR# | 1456100013 | 1456100017 | Average
Diet Lot: # | 111908M | 033009M
Nutrients
Protein (% by wt.) | 17.6 | 17.6 | 17.6
Total Fat (% by wt.) | 6.05 | 5.40 | 5.73
Vitamin A, ppm | 2.71 | 3.44 | 3.08
Vitamin B_1_, ppm | 25.6 | 18.1 | 21.9
Vitamin E, ppm | 27.7 | 32.5 | 30.1
Contaminants
Acrylamide, ppb | <LOQ | <LOQ | <LOQ
Aflatoxin-G_1_, ppb | <MDL | <MDL | <MDL
Aflatoxin-B_1_, ppb | <MDL | <MDL | <MDL
Aflatoxin-B_2_, ppb | <MDL | <MDL | <MDL
Aflatoxin-G_2_, ppb | <MDL | <MDL | <MDL
Total Fumonisin, ppb | 263 | 77 | 170
Volatiles (% by wt.) | 9.05 | 8.70 | 8.88
Pb, ppm | 0.25 | 0 | 0.13
Se, ppm | 0.32 | 0.35 | 0.34
As, ppm | 0.087 | 0.19 | 0.14
Cd, ppm | 0 | 0.16 | 0.08

LOQ = limit of quantification (20 ppm); MDL = method detection limit (0.1 ppb for aflatoxins).

^a^ Analyzed in lots that were used for the study.