# Appendix H Chemical Characteristics and Dose Formulation Studies

## H.1 Procurement and Characterization of Usnea Lichens

Usnea lichen was obtained from Mountain Rose Herbs (Eugene, OR) in bulk shipments and designated as lots 2074 and 4052. Identity, purity, and stability analyses were conducted by the study laboratory. Reports on the analyses performed in support of the Usnea lichens studies are on file at the National Center for Toxicological Research (NCTR).

The lichen lots were examined microscopically and identified as predominantly Usnea scabrata and Usnea cavernosa, using the morphological characteristics provided in the botanical key for identifying lichens.^3,77^ The Usnea scabrata, a rich green material, had generally rounded and highly branched stem formations and the presence of papillae (small bumps or wart-like protrusions with the appearance of “goose bumps”) on the surface of the stems. Usnea cavernosa, a paler green material, had a waxy appearing surface with fewer branches, flat stem, and ridge formations, and pronounced pits.

The Usnea scabrata and Usnea cavernosa were separated from unknown species in each lot of material, cleaned of leaf matter and other debris, and processed in batches of 100–200 g. Total recoveries from each lot are shown in Table H-1. Each batch of lichen was hand ground under liquid nitrogen, dried under vacuum, and sieved progressively into a fine powder using 20-, 40-, and 60-gauge sieves. Samples of the ground preparations of both Usnea scabrata and Usnea cavernosa were analyzed for (+/−)-usnic acid content by the study laboratory using high-performance liquid chromatography (HPLC). HPLC was conducted with a Waters Model 600E HPLC system controller using photodiode array (PDA) detection at 232 nm (Waters Corporation, Milford, MA). The analytical column was a Prodigy ODS-3 (250 mm × 4.6 mm, 5 μM, 100 Å pore size). The isocratic mobile phase was held at 73% acetonitrile, adjusted to pH 3.5 with 0.05% formic acid, for 30 minutes at 1.1 mL/minute and room temperature. This method could not resolve (+)- and (−)-usnic acid. The reported usnic acid content was therefore denoted as (+/−)-usnic acid (CASRN 125-46-2). The lots were found to have similar usnic acid content based on spectrographic comparison to a (+)-usnic acid standard. (+)-Usnic acid (d-usnic acid; 2,6-diacetyl-7,9-dihydroxy-8,9b^®^-dimethyldibenzofuran-1,3(2H,9bH)-dione), CASRN 7562-61-0, lot 02503HD was used for this purpose. It was purchased from Sigma-Aldrich Co. (Milwaukee, WI). Chemical purity (98% per Sigma-Aldrich Certificate of Analysis) was re-evaluated by liquid chromatography–mass spectroscopy (LC/MS) systems including the Quantum Ultra (HPLC −/+ electrospray ionization [ESI]-MS and MS/MS), TSQ7000 (HPLC-PDA/+ESI-MS/MS) and TSQ7000 (gas chromatography [GC]/electron impact [EI]-MS). The LC/MS results were in agreement with proposed fragmentation and literature values.^97^ The GC/EI-MS results showed one component that matched the NIST 2005 library for (+)-usnic acid.

The processed Usnea scabrata from batch 1 had a slightly higher (+/−)-usnic acid content than that of batch 2 (Table H-1). Both batches of Usnea scabrata and both batches of Usnea cavernosa were combined together to provide the Usnea lichens test article. They were blended together in a Patterson-Kelly twin-shell blender with the intensifier bar on for 20 minutes to reach homogeneity. (+/−)-Usnic acid content was determined for the blended material using the HPLC method described above. Nine samples of the final test article were analyzed to confirm homogeneity. The (+/−)-usnic acid content of these averaged 2.78 ± 0.07% by weight (Table H-2). Reanalysis of Usnea lichens powder prepared previously for the 14 day studies demonstrated that the content of (+/−)-usnic acid in powdered Usnea lichens remained stable for up to 2 years when stored dry in the dark at 2°C–8°C. The lichen itself could be stored up to 3 years under similar conditions without loss of (+/−)-usnic acid. Because most lichen secondary metabolites are less polar than (+/−)-usnic acid,^16^ a methanol extract (sonication of 10% suspension for 20 minutes at 23°C) was evaluated by HPLC to determine whether significant amounts of other lichen secondary metabolites were present in the test article (Figure H-2). Nine peaks of unknown metabolites were eluted prior to (+/−)-usnic acid.

The usnic acid chiral content was determined using normal phase HPLC-PDA and by comparison to standards of phenol lichen acids. HPLC was conducted using a Waters Millennium 32 system with PDA detection at 281 nm. The analytical column was a Daicel ChiralPak AS-H amylase-based coated polysaccharide chiral column (250 mm × 4.6 mm, 5 µm) with a Phenomenex 0.5 µm KrudKatcher guard column. The mobile phase (0.9 mL/min) was held at 99.12% hexane:0.8% isopropyl alcohol:ethanol (3:1): 0.08% trifluoroacetic acid for 40 minutes. An authenticated standard of (+)-usnic acid, used as a standard for the chiral separation of (+)- and (−)-usnic acid, was obtained from Chemos Gmbh (Regenstauf, Germany). Pure (−)-usnic acid (2,6-diacetyl-7,9-dihydroxy-8,9b-dimethyldibenzofuran-1,3(2H,9bH)-done, CASRN 125-46-2) could not be obtained commercially, but was identified as the major component of an extract of a sample of the lichen Cladonia unicalis (obtained from the Arizona State University Lichen Herbarium, Phoenix, AZ). HPLC analysis of the Usnea lichen test article indicated that peaks corresponding to both (+)-usnic acid and (−)-usnic acid were present (Figure H-3). Analysis of quadruple samples gave an average chiral composition of 97.5% ± 0.2 and 2.5% ± 0.2, for (+)- and (−)-usnic acid, respectively. Three additional minor peaks were detected by this chromatographic method constituting approximately 0.5% of the total area (Figure H-3).

## H.2 Preparation and Analyses of Dose Formulations

The dose formulations were prepared approximately every 4–8 weeks by hand blending a premix and blending with additional feed in a Patterson-Kelly V-shell blender. Dose formulations were stored in stainless-steel feed cans at 2°C–8°C for up to 12 weeks (Table H-3).

Homogeneity and stability studies were performed on the 15 ppm dose formulations by the study laboratory using the HPLC-PDA method described above. Homogeneity and stability were confirmed for 14 days at room temperature and up to 12 weeks at 2°C–8°C.

Analyses of the dose formulations were conducted using the HPLC-PDA method described above. All dose formulations were analyzed (Table H-4). One formulation was <10% of the target concentration. The formulation was diluted with feed and remixed; the remix was analyzed and found to be within 10% of the target concentration.

Table H-1 Recovery of Usnea scabrata and Usnea cavernosa from Bulk Usnea Lichens in the Three-month Feed Studies

| Batch 1 (Lot 2074) | Batch 2 (Lot 4052)
Total Weight | 3.166 kg | 1.301 kg
Usnea scabrata | 2.530 kg | 1.086 kg
(+/−)-Usnic acid content | [2.83%] | [2.14%]
Usnea cavernosa | 144 g | 15 g
(+/−)-Usnic acid content | [3.81%]^a^ | [3.81%]
Unknown Lichen | 91 g | 21 g
Other Material^b^ | 335 g | 152 g
Total Recovered | 3.100 kg | 1.274 kg
Lost^c^ | 66 g | 27 g

^a^ U. carvernosa from both batches were combined prior to analysis.

^b^ Predominantly tree bark, pine needle, and twigs.

^c^ Included reserve samples of 40 and 10 g, respectively, for the two batches and dust from the processing area that was removed with a vacuum cleaner.

Table H-2 Results of Analysis of (+/−)-Usnic Acid Content in Blended Usnea Lichens Powder Used in the Three-month Feed Studies

Sample^a^ | (+/−)-Usnic Acid Content mg/g (% by Weight)
1 | 27.7 (2.77)
2 | 27.0 (2.70)
3 | 26.9 (2.69)
4 | 28.1 (2.81)
5 | 28.7 (2.87)
6 | 27.5 (2.75)
7 | 28.7 (2.87)
8 | 28.2 (2.82)
9 | 27.6 (2.76)
Mean | 27.8^b^ (2.78)

^a^ Batches 1 and 2 were combined prior to blending into the final test article used here.

^b^ Used to determine weight of lichen to be added to feed to provide required (+/−)-usnic acid ppm doses.

Table H-3 Preparation and Storage of Dose Formulations in the Feed Studies of Usnea Lichens

Preparation
A premix of Usnea lichens and feed was ground by hand with a mortar and pestle and then combined with the remaining feed and blended in a Patterson-Kelly twin-shell blender with the intensifier bar on for 30 minutes. Three batches each of the 15, 30, 50, 120, 180, and 360 ppm dose formulation and two batches of the 720 ppm dose formulations were prepared. One batch of the 180 ppm dose formulation was greater than 10% of the target concentration; the formulation was diluted with feed and remixed. The dose formulations were prepared approximately every 4–8 weeks.
Chemical Lot Number
Lots 2074 and 4052
Storage Conditions
Stored in stainless-steel feed cans at 2°C–8°C
Study Laboratory
National Center for Toxicological Research (Jefferson, AR)

Table H-4 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Feed Studies of Usnea Lichens^a^

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^b^ (ppm) | Difference from Target (%)
Rats and Mice
January 30, 2009 | January 30, 2009 | 15 | 13.5 ± 0.9 | −9.7
February 4, 2009 | February 4, 2009 | 30 | 28.7 ± 0.5 | −4.5
| | 60 | 54.7 ± 1.7 | −8.9
| | 120 | 112 ± 2 | −7
| | 180 | 165 ± 8 | −8.1
| | 360 | 346 ± 10 | −3.8
| | 720 | 701 ± 18 | −2.7
March 17, 2009 | March 17, 2009 | 30 | 29.5 ± 2.6 | −1.8
March 24, 2009 | March 24, 2009 | 60 | 59.8 ± 1.8 | −0.4
| | 360 | 341 ± 4 | −5.3
March 31, 2008 | March 31, 2009 | 15 | 14.5 ± 0.5 | −3.5
| | 120 | 113 ± 3 | −5.9
| | 180 | 154 ± 8^c^ | −14.4
April 6, 2009 | April 6, 2009 | 180 | 164 ± 5^d^ | −9.1
| | 180 | 168 ± 3^d^ | −6.5
April 23, 2009 | April 23, 2009 | 15 | 16.1 ± 0.9 | 7
| | 30 | 27.2 ± 0.5 | −9.5
April 28, 2009 | April 28, 2009 | 60 | 62.8 ± 4.1 | 5
| | 180 | 162 ± 3 | −10
| | 360 | 336 ± 14 | −6.5
May 4, 2009 | May 4, 2009 | 120 | 113 ± 3 | −5.8

^a^ Dose certification based on (+/−)-usnic acid content.

^b^ Results of three analyses (mean ± standard deviation).

^c^ Dose was out of certification and not used.

^d^ Results of remix.

Figure H-1

Micrographs of Usnea scabrata (Left) and Usnea cavernosa (Right)

Figure H-2

Chromatogram of Methanol Extract of the Final Dose Mixture of Usnea Lichens

Peak at 13.147 minutes identified as (+/−)-usnic acid, other peaks not identified.

Figure H-3

Chiral Chromatography of (+/−)-Usnic Acid Extracted from Usnea Lichens