# Appendix G Reproductive Toxicology Studies

Table G-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm^b,c^ | 60 ppm | 120 ppm | 360 ppm
Weights (g)^d^
Necropsy body weight | 337.2 ± 5.9* | 338.2 ± 4.5 | 334.4 ± 5.8 | 316.1 ± 7.2*
L. cauda epididymis | 0.222 ± 0.0052 | 0.224 ± 0.0032 | 0.225 ± 0.0063 | 0.223 ± 0.0030
L. epididymis | 0.509 ± 0.0163 | 0.502 ± 0.0111 | 0.498 ± 0.0117 | 0.498 ± 0.0067
L. testis | 1.606 ± 0.0124 | 1.569 ± 0.0088 | 1.595 ± 0.0175 | 1.639 ± 0.0194
Spermatid Measurements^e^
Spermatid heads (10^6^/g testis) | 170.05 ± 7.51 | 148.52 ± 15.02 | 149.16 ± 9.58 | 154.08 ± 9.11
Spermatid heads (10^6^/testis) | 273.01 ± 12.03 | 232.88 ± 23.25 | 237.82 ± 15.52 | 252.84 ± 15.63
Epididymal Spermatozoal Measurements^e^
Sperm motility (%) | 84.5 ± 1.0 | 83.4 ± 1.3 | 88.0 ± 1.1 | 81.4 ± 1.0
Sperm (10^6^/g cauda epididymis) | 450.2 ± 39.7 | 405.9 ± 25.5 | 401.0 ± 29.3 | 530.0 ± 62.1
Sperm (10^6^/cauda epididymis) | 100.0 ± 9.1 | 90.9 ± 5.7 | 89.6 ± 6.2 | 119.1 ± 14.9

^a^ Lichen concentration in feed standardized to ppm of (+/−)-usnic acid.

^b^ n = 10 for each group.

^c^ Data are presented as mean ± standard error.

^d^ Each exposed group is compared to the control with the William’s test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunnett’s test is applied (* = p ≤ 0.05).

^e^ Each exposed group is compared to the control with Shirley’s test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunn’s test is applied.

Table G-2 Estrous Cycle Characterization for Female Rats in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm^b,c^ | 60 ppm | 120 ppm | 360 ppm
Necropsy Body Weight (g)^d^ | 190.8 ± 3.8 | 198.7 ± 4.0 | 187.1 ± 4.3 | 174.2 ± 2.5***
Proportion of Regular Cycling Females^e^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous Cycle Length (days)^f^ | 5.00 ± 0.00 | 5.00 ± 0.00 | 5.00 ± 0.00 | 5.00 ± 0.00
Estrous Stages (% of cycle)^g^
Diestrus | 58.1 | 62.5 | 60.0 | 59.4
Proestrus | 18.8 | 16.9 | 18.8 | 15.6
Estrus | 21.9* | 20.0 | 20.0 | 23.8**
Metestrus | 0.0 | 0.6 | 1.3 | 0.0
Uncertain diagnosis | 1.3 | 0.0 | 0.0 | 1.3

^a^ Lichen concentration in feed standardized to ppm of (+/−)-usnic acid.

^b^ n = 10 for each group.

^c^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error.

^d^ Statistically evaluated using the William’s and Dunnett’s tests (*** p ≤ 0.001 from the vehicle control group).

^e^ Number of females with a regular cycle/number of females cycling

^f^ Statistically evaluated using the Shirley’s and Dunn’s tests.

^g^ By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated a significantly extended estrus in the 360 ppm group relative to the control group * p ≤ 0.05; ** p ≤ 0.01). No other significant differences in transition probabilities among the groups were observed.

Table G-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm^b,c^ | 60 ppm | 180 ppm | 360 ppm
Weights (g)^d^
Necropsy body weight | 27.9 ± 0.7 | 26.5 ± 0.6 | 27.4 ± 0.5 | 26.1 ± 0.5
L. cauda epididymis | 0.019 ± 0.0011 | 0.020 ± 0.0014 | 0.019 ± 0.0010 | 0.017 ± 0.0006
L. epididymis | 0.049 ± 0.0018* | 0.050 ± 0.0024 | 0.048 ± 0.0021 | 0.043 ± 0.0012*
L. testis | 0.117 ± 0.0022 | 0.119 ± 0.0024 | 0.118 ± 0.0020 | 0.114 ± 0.0018
Spermatid Measurements^e^
Spermatid heads (10^6^/g testis) | 212.07 ± 16.42 | 219.09 ± 15.22 | 233.06 ± 14.19 | 231.37 ± 14.49
Spermatid heads (10^6^/testis) | 24.68 ± 1.82 | 26.20 ± 1.95 | 27.56 ± 1.74 | 26.23 ± 1.50
Epididymal Spermatozoal Measurement^e^
Sperm motility (%) | 80.4 ± 0.54* | 83.2 ± 1.07 | 85.4 ± 1.12** | 84.0 ± 1.57
Sperm (10^6^/g cauda epididymis) | 767.6 ± 57.4 | 845.9 ± 71.8 | 788.7 ± 71.4 | 648.9 ± 61.7
Sperm (10^6^/cauda epididymis) | 14.3 ± 1.4 | 16.6 ± 1.8 | 15.2 ± 1.55 | 11.2 ± 1.20

^a^ Lichen concentration in feed standardized to ppm of (+/−)-usnic acid.

^b^ n = 10 for each group.

^c^ Data are presented as mean ± standard error.

^d^ Each exposed group is compared to the control with the Williams test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunnett’s test is applied (* = p ≤ 0.05).

^e^ Each exposed group is compared to the control with the Shirley test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunn’s test is applied (* = p ≤ 0.05, ** = p ≤ 0.01).

Table G-4 Estrous Cycle Characterization for Female Mice in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm^b,c^ | 60 ppm | 180 ppm | 360 ppm
Necropsy Body Weight (g)^d^ | 23.0 ± 0.6 | 22.7 ± 0.6 | 22.9 ± 0.6 | 20.4 ± 0.3*
Proportion of Regular Cycling Females^e^ | 9/9 | 8/10 | 10/10 | 9/9
Estrous Cycle Length (days)^f^ | 4.2 ± 0.17 | 4.1 ± 0.06 | 4.0 ± 0.06 | 5.3 ± 0.49**
Estrous Stages (% of cycle)^g^
Diestrus | 47.9 | 53.8 | 48.1 | 39.6
Proestrus | 0.0 | 0.6 | 0.0 | 0.7
Estrus | 41.0 | 38.1 | 46.9 | 52.8**
Metestrus | 11.1 | 7.5 | 4.4 | 6.9
Uncertain diagnosis | 0.0 | 0.0 | 0.6 | 0.0

^a^ Lichen concentration in feed standardized to ppm of (+/−)-usnic acid.

^b^ n = 9 for the 0 and 360 groups; n = 10 for the 60 and 180 groups.

^c^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error.

^d^ Statistically evaluated using the William’s and Dunnett’s tests (*p ≤ 0.05 from the vehicle control group).

^e^ Number of females with a regular cycle/number of females cycling.

^f^ Statistically evaluated using Shirley’s and Dunn’s tests (** p ≤ 0.01 from the vehicle control group).

^g^ By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated a significantly extended estrus in the 360 ppm group relative to the control group (** p ≤ 0.01).