# Appendix F Feed Consumption, Target Dose, and Water Consumption

Table F-1 Feed Consumption of Male Rats in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 19.4 ± 0.6 | <0.001 | 10 | 18.4 ± 0.4 | 0.459 | 10 | 18.3 ± 0.3 | 0.373 | 10 | 18.8 ± 0.5 | 0.846 | 10 | 18.3 ± 0.4 | 0.355 | 10 | 15.0 ± 0.5 | < 0.001
2 | 10 | 17.3 ± 0.5 | 0.001 | 10 | 17.2 ± 0.4 | 1.000 | 10 | 17.4 ± 0.5 | 1.000 | 10 | 17.7 ± 0.4 | 0.981 | 10 | 20.0 ± 0.9 | 0.010 | 10 | 19.2 ± 0.9 | 0.125
3 | 10 | 17.0 ± 0.6 | 0.335 | 10 | 18.6 ± 0.8 | 0.563 | 10 | 18.5 ± 0.7 | 0.608 | 10 | 17.5 ± 0.9 | 0.990 | 10 | 19.6 ± 0.5 | 0.111 | 10 | 16.4 ± 1.3 | 0.977
4 | 10 | 18.5 ± 0.4 | <0.001 | 10 | 18.8 ± 0.5 | 0.997 | 10 | 18.1 ± 0.7 | 0.998 | 10 | 19.3 ± 0.4 | 0.895 | 10 | 19.2 ± 0.8 | 0.928 | 10 | 13.2 ± 1.1 | < 0.001
5 | 10 | 20.1 ± 1.4 | 0.025 | 10 | 20.1 ± 1.2 | 1.000 | 10 | 19.2 ± 1.2 | 0.990 | 10 | 20.2 ± 1.0 | 1.000 | 10 | 20.5 ± 1.4 | 1.000 | 9 | 15.3 ± 2.3 | 0.116
6 | 10 | 21.7 ± 1.4 | 0.001 | 10 | 22.0 ± 1.6 | 1.000 | 10 | 20.9 ± 1.4 | 0.993 | 10 | 21.5 ± 1.1 | 1.000 | 10 | 23.0 ± 1.5 | 0.929 | 1 | 9.5 | –
7 | 10 | 22.4 ± 1.1 | – | 10 | 23.1 ± 1.0 | 0.988 | 10 | 21.2 ± 1.0 | 0.896 | 10 | 22.1 ± 0.9 | 1.000 | 10 | 22.8 ± 1.3 | 0.999 | 0 | – ^e^ | –
8 | 10 | 24.8 ± 1.6 | – | 10 | 22.0 ± 1.3 | 0.358 | 10 | 21.7 ± 1.0 | 0.272 | 10 | 23.4 ± 0.9 | 0.902 | 10 | 24.4 ± 1.4 | 0.999 | 0 | – | –
9 | 10 | 24.7 ± 1.1 | – | 10 | 21.6 ± 1.2 | 0.250 | 10 | 24.1 ± 1.2 | 0.997 | 10 | 22.5 ± 1.5 | 0.555 | 10 | 24.0 ± 0.8 | 0.993 | 0 | – | –
10 | 10 | 22.6 ± 1.4 | – | 10 | 21.5 ± 0.8 | 0.925 | 10 | 21.9 ± 1.0 | 0.992 | 10 | 22.6 ± 1.2 | 1.000 | 10 | 22.4 ± 0.7 | 1.000 | 0 | – | –
11 | 10 | 21.3 ± 0.9 | – | 10 | 22.7 ± 0.7 | 0.707 | 10 | 21.9 ± 0.9 | 0.989 | 10 | 22.2 ± 0.9 | 0.947 | 10 | 22.8 ± 1.0 | 0.653 | 0 | – | –
12 | 10 | 20.9 ± 1.0 | – | 10 | 22.0 ± 0.5 | 0.885 | 10 | 22.4 ± 1.0 | 0.653 | 10 | 21.9 ± 1.0 | 0.913 | 10 | 22.6 ± 1.0 | 0.540 | 0 | – | –
13 | 10 | 24.0 ± 1.0 | – | 10 | 23.8 ± 0.9 | 1.000 | 10 | 22.8 ± 1.3 | 0.897 | 10 | 22.8 ± 1.2 | 0.879 | 10 | 24.0 ± 0.9 | 1.000 | 0 | – | –
Mean for Weeks
1–13 | | 21.1 ± 0.4 | – | | 20.9 ± 0.4 | 0.984 | | 20.7 ± 0.4 | 0.826 | | 21.0 ± 0.4 | 0. 995 | | 21.8 ± 0.4 | 0.568 | – | – | –

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the exposed columns are Dunnett's adjusted p values for pairwise comparisons of the exposed groups to the 0 ppm group.

^e^ No data collected.

Table F-2 Feed Consumption of Female Rats in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 13.5 ± 0.4 | <0.001 | 10 | 14.2 ± 0.8 | 0.931 | 10 | 14.0 ± 0.7 | 0.978 | 10 | 13.8 ± 0.7 | 0.997 | 10 | 12.5 ± 0.4 | 0.720 | 10 | 10.6 ± 0.8 | 0.009
2 | 10 | 13.7 ± 0.6 | 0.585 | 10 | 14.3 ± 0.9 | 0.991 | 10 | 14.1 ± 0.4 | 0.999 | 10 | 14.2 ± 0.5 | 0.998 | 10 | 14.3 ± 0.7 | 0.988 | 10 | 14.6 ± 1.8 | 0.950
3 | 10 | 14.0 ± 0.5 | 0.015 | 10 | 13.0 ± 0.6 | 0.912 | 10 | 14.1 ± 0.7 | 1.000 | 10 | 15.3 ± 0.8 | 0.717 | 10 | 14.4 ± 0.7 | 0.998 | 10 | 11.2 ± 1.5 | 0.092
4 | 10 | 14.2 ± 0.9 | 0.871 | 10 | 13.5 ± 0.5 | 0.996 | 10 | 15.0 ± 1.1 | 0.991 | 10 | 15.9 ± 0.7 | 0.857 | 10 | 14.6 ± 0.4 | 1.000 | 10 | 14.7 ± 2.8 | 0.999
5 | 10 | 16.0 ± 1.5 | 0.567 | 10 | 15.6 ± 1.3 | 1.000 | 10 | 17.8 ± 1.4 | 0.823 | 10 | 16.3 ± 1.2 | 1.000 | 10 | 16.2 ± 0.9 | 1.000 | 6 | 13.9 ± 2.6 | 0.997
6 | 10 | 16.4 ± 1.0 | 0.956 | 10 | 15.3 ± 0.9 | 0.987 | 10 | 17.6 ± 1.6 | 0.975 | 10 | 19.5 ± 2.2 | 0.484 | 10 | 18.2 ± 1.8 | 0.876 | 1 | 16.6 | 1.000
7 | 10 | 15.8 ± 1.0 | 0.833 | 10 | 18.3 ± 1.5 | 0.616 | 10 | 17.9 ± 1.6 | 0.773 | 10 | 18.9 ± 1.7 | 0.430 | 10 | 16.9 ± 1.4 | 0.980 | 1 | 16.6 | 1.000
8 | 10 | 16.2 ± 0.9 | 0.157 | 10 | 17.7 ± 1.2 | 0.850 | 10 | 18.7 ± 1.5 | 0.417 | 10 | 17.7 ± 0.9 | 0.823 | 10 | 17.5 ± 1.2 | 0.901 | 1 | 22.7 | 0.303
9 | 10 | 16.2 ± 0.7 | <0.001 | 10 | 16.8 ± 1.1 | 0.990 | 10 | 17.7 ± 0.8 | 0.682 | 10 | 18.0 ± 1.0 | 0.506 | 10 | 19.1 ± 1.0 | 0.112 | 1 | 33.2 | <0.001
10 | 10 | 15.9 ± 0.7 | 0.236 | 10 | 16.2 ± 1.0 | 0.999 | 10 | 19.0 ± 1.3 | 0.135 | 10 | 16.5 ± 1.0 | 0.994 | 10 | 18.5 ± 1.2 | 0.298 | 1 | 20.4 | 0.562
11 | 10 | 16.2 ± 0.6 | 0.074 | 10 | 15.4 ± 0.4 | 0.929 | 10 | 17.4 ± 0.9 | 0.829 | 10 | 16.6 ± 1.1 | 0.998 | 10 | 17.2 ± 1.1 | 0.899 | 1 | 21.1 | 0.309
12 | 10 | 15.6 ± 0.8 | 0.988 | 10 | 16.4 ± 0.9 | 0.976 | 10 | 17.7 ± 0.8 | 0.442 | 10 | 17.6 ± 1.4 | 0.504 | 10 | 16.4 ± 1.0 | 0.972 | 1 | 16.6 | 0.998
13 | 10 | 16.5 ± 0.8 | 0.105 | 10 | 17.7 ± 0.7 | 0.795 | 10 | 19.4 ± 0.6 | 0.074 | 10 | 17.5 ± 0.9 | 0.872 | 10 | 17.5 ± 1.1 | 0.900 | 1 | 22.2 | 0.162
Mean for Weeks
1–13 | | 15.4 ± 0.5 | 0.066 | | 15.7 ± 0.5 | 0.985 | | 16.9 ± 0.5 | 0.080 | | 16.7 ± 0.5 | 0.158 | | 16.4 ± 0.5 | 0.418 | | 18.2 ± 1.1 | 0.109

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the exposed columns are Dunnett's adjusted p values for pairwise comparisons of the exposed groups to the 0 ppm group.

Table F-3 Feed Consumption of Male Mice in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 5.9 ± 0.3 | 0.406 | 10 | 6.2 ± 0.7 | 0.999 | 10 | 6.0 ± 0.6 | 1.000 | 10 | 5.9 ± 0.7 | 1.000 | 10 | 5.5 ± 0.3 | 0.979 | 10 | 5.6 ± 0.5 | 0.989
2 | 10 | 6.0 ± 0.3 | 0.649 | 10 | 6.9 ± 0.9 | 0.519 | 10 | 5.6 ± 0.3 | 0.972 | 10 | 6.2 ± 0.3 | 0.999 | 10 | 6.7 ± 0.5 | 0.739 | 10 | 6.3 ± 0.5 | 0.987
3 | 10 | 6.4 ± 0.6 | 0.329 | 10 | 7.0 ± 0.8 | 0.966 | 10 | 6.1 ± 0.7 | 0.998 | 10 | 5.8 ± 0.3 | 0.957 | 10 | 7.5 ± 0.8 | 0.659 | 10 | 6.9 ± 0.7 | 0.979
4 | 10 | 5.9 ± 0.6 | 0.375 | 10 | 7.2 ± 0.7 | 0.561 | 10 | 7.3 ± 0.8 | 0.464 | 10 | 6.3 ± 0.5 | 0.996 | 10 | 7.2 ± 0.7 | 0.549 | 10 | 7.3 ± 0.8 | 0.499
5 | 10 | 6.8 ± 0.5 | 0.655 | 10 | 6.6 ± 0.5 | 1.000 | 10 | 7.0 ± 0.7 | 1.000 | 10 | 6.6 ± 0.5 | 0.999 | 10 | 7.5 ± 0.7 | 0.900 | 10 | 6.9 ± 0.7 | 1.000
6 | 10 | 7.2 ± 0.6 | 0.042 | 10 | 6.6 ± 0.4 | 0.963 | 10 | 6.7 ± 0.5 | 0.988 | 10 | 6.3 ± 0.3 | 0.767 | 10 | 8.2 ± 0.7 | 0.636 | 10 | 8.0 ± 1.0 | 0.846
7 | 10 | 7.5 ± 0.5 | 0.676 | 10 | 6.3 ± 0.6 | 0.306 | 10 | 6.8 ± 0.6 | 0.744 | 10 | 5.7 ± 0.2 | 0.051 | 10 | 7.4 ± 0.7 | 1.000 | 10 | 6.3 ± 0.4 | 0.281
8 | 10 | 8.4 ± 0.9 | 0.776 | 10 | 6.5 ± 0.7 | 0.232 | 10 | 7.0 ± 0.7 | 0.497 | 10 | 6.7 ± 0.5 | 0.326 | 10 | 7.6 ± 0.8 | 0.918 | 10 | 7.4 ± 0.9 | 0.806
9 | 10 | 5.7 ± 0.3 | 0.028 | 10 | 6.1 ± 0.6 | 0.993 | 10 | 6.2 ± 0.3 | 0.966 | 10 | 6.6 ± 0.6 | 0.713 | 10 | 6.7 ± 0.6 | 0.625 | 10 | 7.5 ± 0.9 | 0.133
10 | 10 | 6.5 ± 0.4 | 0.438 | 10 | 6.9 ± 0.7 | 0.959 | 10 | 6.0 ± 0.4 | 0.965 | 10 | 6.8 ± 0.6 | 0.984 | 10 | 6.7 ± 0.5 | 0.994 | 10 | 6.0 ± 0.5 | 0.948
11 | 10 | 6.5 ± 0.4 | 0.180 | 10 | 6.0 ± 0.4 | 0.969 | 10 | 6.9 ± 0.5 | 0.995 | 10 | 7.7 ± 0.7 | 0.551 | 10 | 6.7 ± 0.7 | 0.999 | 10 | 7.6 ± 0.9 | 0.596
12 | 10 | 8.8 ± 0.8 | 0.180 | 10 | 6.0 ± 0.3 | 0.012 | 10 | 6.2 ± 0.2 | 0.021 | 10 | 7.2 ± 0.7 | 0.288 | 10 | 8.0 ± 0.8 | 0.864 | 10 | 8.0 ± 0.7 | 0.849
13 | 10 | 8.5 ± 0.6 | 0.005 | 10 | 7.7 ± 0.4 | 0.870 | 10 | 7.6 ± 0.5 | 0.792 | 10 | 8.2 ± 0.5 | 0.997 | 10 | 9.6 ± 1.0 | 0.632 | 10 | 9.9 ± 0.7 | 0.447
Mean for Weeks
1–13 | | 6.9 ± 0.2 | 0.004 | | 6.6 ± 0.2 | 0.608 | | 6.6 ± 0.2 | 0.481 | | 6.6 ± 0.2 | 0.599 | | 7.4 ± 0.2 | 0.347 | | 7.2 ± 0.2 | 0.757

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the exposed columns are Dunnett's adjusted p values for pairwise comparisons of the exposed groups to the 0 ppm group.

Table F-4 Feed Consumption of Female Mice in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | p Value^d^ | N | Mean ± SE | p Value | N | Mean ± SE | p Value | N | Mean ± SE | p Value | N | Mean ± SE | p Value | N | Mean ± SE | p Value
1 | 10 | 7.2 ± 0.9 | 0.311 | 10 | 6.1 ± 0.6 | 0.572 | 10 | 6.2 ± 0.5 | 0.679 | 10 | 6.1 ± 0.5 | 0.576 | 10 | 6.4 ± 0.5 | 0.784 | 10 | 5.8 ± 0.7 | 0.323
2 | 10 | 6.3 ± 0.7 | 0.644 | 10 | 7.1 ± 0.7 | 0.881 | 10 | 6.9 ± 0.9 | 0.974 | 10 | 6.0 ± 0.4 | 0.998 | 10 | 6.4 ± 0.5 | 1.000 | 10 | 7.1 ± 0.9 | 0.897
3 | 10 | 6.8 ± 0.7 | 0.540 | 10 | 7.0 ± 0.4 | 1.000 | 10 | 7.2 ± 0.5 | 0.994 | 10 | 6.0 ± 0.3 | 0.905 | 10 | 7.4 ± 1.4 | 0.981 | 10 | 6.2 ± 0.6 | 0.951
4 | 10 | 7.2 ± 0.7 | 0.563 | 10 | 7.3 ± 0.7 | 1.000 | 10 | 6.7 ± 0.6 | 0.975 | 10 | 6.6 ± 0.7 | 0.930 | 10 | 6.3 ± 0.6 | 0.757 | 9 | 6.8 ± 0.7 | 0.986
5 | 10 | 7.2 ± 0.8 | 0.040 | 10 | 7.2 ± 0.5 | 1.000 | 10 | 6.1 ± 0.2 | 0.809 | 10 | 7.1 ± 0.9 | 1.000 | 10 | 7.5 ± 0.6 | 0.996 | 9 | 8.7 ± 1.2 | 0.476
6 | 10 | 7.0 ± 0.6 | 0.826 | 10 | 6.7 ± 0.6 | 0.996 | 10 | 7.5 ± 0.6 | 0.981 | 10 | 7.3 ± 0.6 | 0.999 | 10 | 7.1 ± 0.7 | 1.000 | 9 | 7.2 ± 0.3 | 0.999
7 | 10 | 7.3 ± 0.5 | 0.038 | 10 | 7.6 ± 1.1 | 0.999 | 10 | 6.7 ± 0.5 | 0.889 | 10 | 7.7 ± 0.5 | 0.993 | 10 | 5.4 ± 0.3 | 0.103 | 9 | 6.2 ± 0.3 | 0.579
8 | 10 | 7.9 ± 1.0 | 0.502 | 10 | 6.4 ± 0.6 | 0.710 | 10 | 8.1 ± 1.2 | 1.000 | 10 | 6.8 ± 0.7 | 0.890 | 10 | 7.2 ± 1.1 | 0.985 | 9 | 8.2 ± 0.9 | 1.000
9 | 9 | 6.8 ± 0.5 | 0.049 | 10 | 6.3 ± 0.5 | 0.917 | 10 | 6.5 ± 0.4 | 0.983 | 10 | 7.9 ± 0.7 | 0.615 | 10 | 6.5 ± 0.5 | 0.985 | 9 | 8.3 ± 0.8 | 0.328
10 | 9 | 6.8 ± 0.8 | 0.206 | 10 | 7.2 ± 0.9 | 0.997 | 10 | 8.2 ± 0.8 | 0.571 | 10 | 7.9 ± 0.8 | 0.727 | 10 | 6.4 ± 0.8 | 0.996 | 9 | 6.5 ± 0.4 | 0.999
11 | 9 | 7.2 ± 0.7 | 0.740 | 10 | 7.1 ± 0.8 | 1.000 | 10 | 7.5 ± 0.8 | 0.998 | 10 | 8.2 ± 0.3 | 0.790 | 10 | 8.2 ± 0.8 | 0.778 | 9 | 7.5 ± 0.7 | 0.999
12 | 9 | 7.4 ± 0.4 | 0.334 | 10 | 7.9 ± 0.6 | 0.976 | 10 | 7.4 ± 0.7 | 1.000 | 10 | 8.4 ± 0.6 | 0.686 | 10 | 7.6 ± 0.7 | 1.000 | 9 | 8.5 ± 0.7 | 0.649
13 | 9 | 8.5 ± 1.0 | 0.336 | 10 | 9.9 ± 0.8 | 0.469 | 10 | 8.2 ± 0.6 | 0.999 | 10 | 9.0 ± 0.6 | 0.983 | 10 | 8.5 ± 0.5 | 1.000 | 9 | 9.9 ± 0.8 | 0.524
Mean for Weeks
1–13 | | 7.2 ± 0.2 | 0.555 | | 7.2 ± 0.2 | 1.000 | | 7.2 ± 0.2 | 1.000 | | 7.3 ± 0.2 | 0.998 | | 7.0 ± 0.2 | 0.924 | | 7.4 ± 0.2 | 0.914

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the exposed columns are Dunnett's adjusted p values for pairwise comparisons of the exposed groups to the 0 ppm group.

Table F-5 Target and Observed Doses of (+/−)-Usnic Acid in Rats Exposed to Usnea Lichens in the Three-month Feed Study

Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Lichen Dosed (ppm)^d^ | Observed Dose (mg/kg/day)^e^
Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Lichen Dosed (ppm)^d^ | Females | Males
30 | 2.5 | 1,079 | 2.59 ± 0.05 93^f^ | 2.14 ± 0.04 77
60 | 5 | 2,158 | 5.38 ± 0.08 194 | 4.21 ± 0.10 151
120 | 10 | 4,317 | 11.14 ± 0.21 401 | 8.70 ± 0.21 313
360 | 30 | 12,950 | 34.2 ± 0.63 1,230 | 28.3 ± 0.61 1,018
720 | 60 | 25,899 | 83.5 ± 5.36 3,004 | 69.9 ± 4.52^g^ 2,514

^a^ Feed concentrations are denoted by their (+/−)-usnic acid content as ppm added to feed.

^b^ Doses were selected based on data obtained from 14-day feed studies (Appendix J) and historical data for the animal colonies.

^c^ Target dose estimate was calculated from historical body weight and feed consumption data for the animal colonies.

^d^ Lichen concentration in the feed required to provide target dose.

^e^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving rats in each dosed group. Observed feed consumption values do not correct for spillage. Data presented as mean ± standard error for the 13 weekly values.

^f^ Observed dose of Usnea lichens calculated from the mean (+/−)-usnic acid dose.

^g^ Data for 6 weeks only.

Table F-6 Target and Observed Doses of (+/−)-Usnic Acid in Mice Exposed to Usnea Lichens in the Three-month Feed Study

Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Lichen Dosed (ppm)^d^ | Observed Dose (mg/kg/day)^e^
Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Lichen Dosed (ppm)^d^ | Females | Males
15 | 2.5 | 540 | 4.84 ± 0.14 174^f^ | 3.72 ± 0.12 134
30 | 5 | 1,079 | 9.91 ± 0.22 356 | 7.34 ± 0.18 264
60 | 10 | 2,158 | 19.84 ± 0.35 714 | 15.01 ± 0.26 540
180 | 30 | 6,475 | 57.61 ± 1.70 2,012 | 50.7 ± 1.41 1,824
360 | 60 | 12,950 | 136.6 ± 4.70 4,914 | 104.4 ± 3.06 3,755

^a^ Feed concentrations are denoted by their (+/−)-usnic acid content as ppm added to feed.

^b^ Doses were selected based on data obtained from 14-day feed studies (Appendix J) and historical data for the animal colonies.

^c^ Target dose estimate was calculated from historical body weight and feed consumption data for the animal colonies.

^d^ Lichen concentration in the feed required to provide target dose.

^e^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving rats in each dosed group. Observed feed consumption values do not correct for spillage. Data presented as mean ± standard error for the 13 weekly values.

^f^ Observed dose of Usnea lichens calculated from the mean (+/−)-usnic acid dose.

Table F-7 Water Consumption of Male Rats in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 23.8 ± 0.8 | 0.227 | 10 | 24.6 ± 1.1 | 0.980 | 10 | 23.9 ± 1.4 | 1.000 | 10 | 25.6 ± 1.1 | 0.648 | 10 | 24.0 ± 1.0 | 1.000 | 10 | 22.8 ± 0.9 | 0.940
2 | 10 | 22.3 ± 0.6 | 0.000 | 10 | 22.3 ± 0.8 | 1.000 | 10 | 22.6 ± 0.9 | 1.000 | 10 | 22.7 ± 0.8 | 1.000 | 10 | 26.2 ± 2.2 | 0.070 | 10 | 26.4 ± 0.7 | 0.047
3 | 10 | 20.7 ± 0.5 | 0.000 | 10 | 22.9 ± 0.7 | 0.200 | 10 | 22.0 ± 0.9 | 0.643 | 10 | 22.1 ± 0.8 | 0.604 | 10 | 23.8 ± 0.8 | 0.025 | 10 | 27.7 ± 1.1 | 0.000
4 | 10 | 22.8 ± 1.5 | 0.000 | 10 | 24.9 ± 1.6 | 0.749 | 10 | 21.7 ± 0.3 | 0.975 | 10 | 24.2 ± 2.0 | 0.925 | 10 | 27.5 ± 1.1 | 0.077 | 10 | 29.3 ± 1.3 | 0.006
5 | 10 | 21.8 ± 1.2 | 0.441 | 10 | 21.2 ± 0.7 | 0.996 | 10 | 21.3 ± 1.0 | 0.998 | 10 | 23.1 ± 1.2 | 0.894 | 10 | 27.8 ± 1.6 | 0.002 | 9 | 21.1 ± 1.2 | 0.993
6 | 10 | 22.0 ± 0.5 | 0.167 | 10 | 21.2 ± 0.7 | 0.960 | 10 | 21.6 ± 1.0 | 0.999 | 10 | 24.8 ± 0.9 | 0.068 | 10 | 27.2 ± 1.0 | 0.000 | 1 | 24.1 | 0.856
7 | 10 | 21.6 ± 0.6 | – | 10 | 21.1 ± 0.7 | 0.999 | 10 | 22.2 ± 0.8 | 0.999 | 10 | 24.8 ± 1.4 | 0.365 | 10 | 28.5 ± 2.6 | 0.003 | 0 | –^e^ | –
8 | 10 | 23.4 ± 1.7 | – | 10 | 21.3 ± 0.7 | 0.517 | 10 | 21.4 ± 0.8 | 0.562 | 10 | 23.4 ± 0.8 | 1.000 | 10 | 25.2 ± 0.8 | 0.617 | 0 | – | –
9 | 10 | 20.5 ± 0.8 | – | 10 | 22.3 ± 1.2 | 0.735 | 10 | 21.0 ± 0.8 | 0.998 | 10 | 24.7 ± 2.1 | 0.061 | 10 | 24.7 ± 0.6 | 0.059 | 0 | – | –
10 | 10 | 20.7 ± 0.6 | – | 10 | 21.6 ± 1.4 | 0.965 | 10 | 20.4 ± 0.5 | 1.000 | 10 | 22.3 ± 1.0 | 0.691 | 10 | 26.3 ± 1.2 | 0.001 | 0 | – | –
11 | 10 | 20.8 ± 0.5 | – | 10 | 21.3 ± 0.8 | 0.985 | 10 | 20.5 ± 0.7 | 0.999 | 10 | 21.6 ± 1.1 | 0.900 | 10 | 25.5 ± 0.7 | 0.000 | 0 | – | –
12 | 10 | 20.6 ± 0.9 | – | 10 | 23.4 ± 2.1 | 0.618 | 10 | 22.9 ± 2.4 | 0.768 | 10 | 20.6 ± 0.8 | 1.000 | 10 | 25.8 ± 1.0 | 0.080 | 0 | – | –
13 | 10 | 21.4 ± 0.5 | – | 10 | 22.5 ± 0.7 | 0.776 | 10 | 21.0 ± 0.7 | 0.994 | 10 | 23.0 ± 1.1 | 0.441 | 10 | 25.9 ± 0.7 | 0.000 | 0 | – | –
Mean for Weeks
1–13 | | 21.7 ± 0.4 | – | | 22.3 ± 0.4 | 0.622 | | 21.7 ± 0.4 | 1.000 | | 23.3 ± 0.4 | 0.022 | | 26.0 ± 0.4 | 0.000 | – | – | –

^a^ Water changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the exposed columns are Dunnett's adjusted p values for pairwise comparisons of the exposed groups to the 0 ppm group.

^e^ No data collected.

Table F-8 Water Consumption of Female Rats in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 22.7 ± 1.3 | 0.009 | 10 | 23.6 ± 2.4 | 0.989 | 10 | 22.1 ± 1.2 | 0.999 | 10 | 21.3 ± 1.1 | 0.953 | 10 | 22.5 ± 0.9 | 1.000 | 10 | 17.8 ± 1.6 | 0.083
2 | 10 | 22.0 ± 1.8 | 0.271 | 10 | 20.7 ± 0.8 | 0.902 | 10 | 21.4 ± 0.9 | 0.995 | 10 | 22.3 ± 1.4 | 1.000 | 10 | 21.7 ± 0.8 | 1.000 | 10 | 19.9 ± 1.1 | 0.574
3 | 10 | 20.5 ± 1.2 | 0.021 | 10 | 19.8 ± 0.6 | 0.989 | 10 | 22.0 ± 0.7 | 0.705 | 10 | 21.8 ± 1.4 | 0.785 | 10 | 20.8 ± 0.4 | 1.000 | 10 | 18.1 ± 1.2 | 0.287
4 | 10 | 20.6 ± 0.7 | 0.580 | 10 | 20.3 ± 0.7 | 1.000 | 10 | 21.4 ± 0.9 | 0.982 | 10 | 20.8 ± 1.2 | 1.000 | 10 | 23.4 ± 1.8 | 0.232 | 10 | 19.2 ± 0.6 | 0.843
5 | 10 | 21.2 ± 1.2 | 0.476 | 10 | 20.0 ± 0.8 | 0.981 | 10 | 20.5 ± 1.1 | 0.999 | 10 | 20.8 ± 1.3 | 1.000 | 10 | 25.8 ± 1.8 | 0.122 | 6 | 21.0 ± 3.7 | 1.000
6 | 10 | 21.2 ± 1.2 | 0.000 | 10 | 19.1 ± 1.0 | 0.395 | 10 | 20.9 ± 0.7 | 1.000 | 10 | 20.2 ± 0.8 | 0.928 | 10 | 23.4 ± 0.9 | 0.339 | 1 | 35.2 | 0.000
7 | 10 | 19.8 ± 0.5 | 0.014 | 10 | 19.7 ± 0.9 | 1.000 | 10 | 20.4 ± 0.6 | 0.974 | 10 | 19.1 ± 0.8 | 0.938 | 10 | 22.9 ± 0.9 | 0.017 | 1 | 25.2 | 0.150
8 | 10 | 19.7 ± 1.1 | 0.071 | 10 | 18.4 ± 0.6 | 0.964 | 10 | 23.1 ± 3.1 | 0.391 | 10 | 18.9 ± 0.5 | 0.996 | 10 | 22.0 ± 0.8 | 0.732 | 1 | 28.6 | 0.292
9 | 10 | 20.5 ± 1.0 | 0.326 | 10 | 20.7 ± 1.5 | 1.000 | 10 | 18.2 ± 0.5 | 0.364 | 10 | 18.5 ± 0.5 | 0.495 | 10 | 22.5 ± 1.2 | 0.525 | 1 | 15.7 | 0.469
10 | 10 | 18.2 ± 0.9 | 0.019 | 10 | 20.1 ± 1.4 | 0.419 | 10 | 19.9 ± 0.7 | 0.533 | 10 | 18.6 ± 0.6 | 0.999 | 10 | 22.7 ± 0.7 | 0.003 | 1 | 25.2 | 0.084
11 | 10 | 20.3 ± 1.2 | 0.034 | 10 | 18.1 ± 0.6 | 0.290 | 10 | 20.0 ± 0.9 | 0.999 | 10 | 20.3 ± 0.6 | 1.000 | 10 | 24.4 ± 1.1 | 0.007 | 1 | 24.4 | 0.501
12 | 10 | 19.2 ± 0.9 | 0.427 | 10 | 19.1 ± 0.5 | 1.000 | 10 | 25.9 ± 3.5 | 0.091 | 10 | 22.9 ± 2.4 | 0.588 | 10 | 22.0 ± 1.5 | 0.802 | 1 | 26.4 | 0.740
13 | 10 | 22.9 ± 1.4 | 0.364 | 10 | 25.2 ± 3.7 | 0.866 | 10 | 22.6 ± 0.9 | 1.000 | 10 | 24.1 ± 1.2 | 0.988 | 10 | 25.4 ± 0.7 | 0.824 | 1 | 28.8 | 0.817
Mean for Weeks
1–13 | | 20.7 ± 0.4 | 0.007 | | 20.4 ± 0.4 | 0.987 | | 21.4 ± 0.4 | 0.640 | | 20.7 ± 0.4 | 1.000 | | 23.0 ± 0.4 | 0.001 | | 23.3 ± 1.1 | 0.116

^a^ Water changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the exposed columns are Dunnett's adjusted p values for pairwise comparisons of the exposed groups to the 0 ppm group.