# Appendix D Body Weights

Table D-1 Body Weights of Male Rats in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 196.4 ± 3.8 | 10 | 195.9 ± 3.9 | | 10 | 194.6 ± 3.6 | | 10 | 201.6 ± 7.1 | | 10 | 195.2 ± 5.0 | | 10 | 195.5 ± 4.9
1 | 10 | 217.4 ± 3.7*** | 10 | 218.9 ± 4.4 | 100.7 | 10 | 215.2 ± 3.8 | 99.0 | 10 | 213.5 ± 4.6 | 98.2 | 10 | 210.9 ± 4.2 | 97.0 | 10 | 184.8 ± 5.2*** | 85.0
2 | 10 | 234.4 ± 4.9*** | 10 | 234.9 ± 5.5 | 100.2 | 10 | 230.9 ± 3.7 | 98.5 | 10 | 228.7 ± 4.3 | 97.6 | 10 | 224.0 ± 4.8 | 95.6 | 10 | 181.6 ± 4.1*** | 77.5
3 | 10 | 246.9 ± 3.9*** | 10 | 250.9 ± 5.2 | 101.6 | 10 | 249.7 ± 4.1 | 101.1 | 10 | 244.8 ± 4.6 | 99.1 | 10 | 242.8 ± 5.7 | 98.3 | 10 | 161.2 ± 5.3*** | 65.3
4 | 10 | 263.7 ± 4.1*** | 10 | 265.2 ± 4.6 | 100.6 | 10 | 266.1 ± 4.3 | 100.9 | 10 | 260.1 ± 5.0 | 98.6 | 10 | 251.8 ± 5.0 | 95.5 | 10 | 139.9 ± 5.0*** | 53.1
5 | 10 | 277.8 ± 4.0*** | 10 | 278.7 ± 5.0 | 100.3 | 10 | 281.1 ± 4.6 | 101.2 | 10 | 273.5 ± 5.0 | 98.5 | 10 | 262.0 ± 5.7* | 94.3 | 9 | 127.8 ± 2.3*** | 46.0
6 | 10 | 292.0 ± 4.8*** | 10 | 295.7 ± 4.8 | 101.3 | 10 | 292.9 ± 5.3 | 100.3 | 10 | 289.5 ± 5.2 | 99.1 | 10 | 274.5 ± 5.8* | 94.0 | 1 | 119.6*** | 41.0
7 | 10 | 304.3 ± 4.8** | 10 | 302.7 ± 4.8 | 99.5 | 10 | 306.5 ± 4.8 | 100.7 | 10 | 302.2 ± 4.7 | 99.3 | 10 | 288.2 ± 6.3 | 94.7 | 0 | –^e^ | –
8 | 10 | 312.8 ± 4.3*** | 10 | 311.2 ± 4.8 | 99.5 | 10 | 314.6 ± 3.7 | 100.6 | 10 | 310.5 ± 3.8 | 99.3 | 10 | 295.7 ± 6.4* | 94.5 | 0 | – | –
9 | 10 | 321.8 ± 5.4*** | 10 | 320.6 ± 4.4 | 99.6 | 10 | 325.1 ± 4.5 | 101.0 | 10 | 319.1 ± 4.6 | 99.2 | 10 | 303.1 ± 6.5* | 94.2 | 0 | – | –
10 | 10 | 330.9 ± 5.7*** | 10 | 331.0 ± 4.7 | 100.0 | 10 | 334.2 ± 4.7 | 101.0 | 10 | 328.2 ± 5.2 | 99.2 | 10 | 310.7 ± 6.6* | 93.9 | 0 | – | –
11 | 10 | 338.7 ± 5.5*** | 10 | 338.9 ± 4.8 | 100.1 | 10 | 342.4 ± 4.5 | 101.1 | 10 | 335.3 ± 5.1 | 99.0 | 10 | 318.4 ± 7.1* | 94.0 | 0 | – | –
12 | 10 | 344.2 ± 6.3** | 10 | 343.6 ± 5.6 | 99.8 | 10 | 348.2 ± 5.0 | 101.2 | 10 | 342.1 ± 5.9 | 99.4 | 10 | 324.8 ± 7.5 | 94.4 | 0 | – | –
13 | 10 | 352.6 ± 5.9** | 10 | 351.3 ± 5.9 | 99.6 | 10 | 353.9 ± 4.7 | 100.4 | 10 | 350.0 ± 5.9 | 99.3 | 10 | 331.9 ± 7.3* | 94.1 | 0 | – | –
Mean for Weeks
1–13 | | 295.4 ± 3.8** | | 296.2 ± 3.8 | 100.3 | | 298.4 ± 3.8 | 101.0 | | 288.8 ± 3.8 | 97.8 | | 280.9 ± 3.8* | 95.1

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant exposure trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^d^ Mean weight as percentage of control.

^e^ No data collected.

Table D-2 Body Weights of Female Rats in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 140.0 ± 2.4 | 10 | 141.5 ± 3.3 | | 10 | 145.2 ± 2.5 | | 10 | 141.1 ± 3.2 | | 10 | 141.5 ± 2.7 | | 10 | 139.6 ± 2.1
1 | 10 | 150.2 ± 2.3*** | 10 | 149.6 ± 3.8 | 99.6 | 10 | 153.5 ± 2.9 | 102.2 | 10 | 147.9 ± 2.8 | 98.5 | 10 | 146.4 ± 2.6* | 97.5 | 10 | 126.1 ± 2.7*** | 84.0
2 | 10 | 156.4 ± 2.3*** | 10 | 157.9 ± 4.6 | 101.0 | 10 | 162.6 ± 4.5 | 104.0 | 10 | 156.1 ± 3.2 | 99.8 | 10 | 152.4 ± 2.8 | 97.4 | 10 | 122.1 ± 4.0*** | 78.1
3 | 10 | 165.1 ± 2.7*** | 10 | 164.3 ± 3.8 | 99.5 | 10 | 170.8 ± 3.7 | 103.5 | 10 | 165.4 ± 3.1 | 100.2 | 10 | 159.1 ± 2.5 | 96.4 | 10 | 111.9 ± 6.4*** | 67.8
4 | 10 | 172.9 ± 2.8*** | 10 | 170.2 ± 4.1 | 98.4 | 10 | 176.9 ± 3.8 | 102.3 | 10 | 170.1 ± 3.5 | 98.4 | 10 | 164.8 ± 2.5 | 95.3 | 10 | 102.3 ± 7.2*** | 59.2
5 | 10 | 178.3 ± 3.0*** | 10 | 176.6 ± 4.7 | 99.0 | 10 | 182.8 ± 3.9 | 102.5 | 10 | 176.1 ± 3.6 | 98.8 | 10 | 169.6 ± 2.5 | 95.1 | 6 | 105.0 ± 13.3*** | 58.9
6 | 10 | 182.4 ± 3.3*** | 10 | 181.1 ± 4.8 | 99.3 | 10 | 188.0 ± 3.9 | 103.1 | 10 | 181.6 ± 4.9 | 99.6 | 10 | 172.5 ± 2.2** | 94.6 | 1 | 174.0*** | 95.4
7 | 10 | 186.9 ± 4.0*** | 10 | 186.3 ± 4.9 | 99.7 | 10 | 193.9 ± 3.8 | 103.7 | 10 | 185.3 ± 4.2 | 99.1 | 10 | 175.8 ± 2.6*** | 94.1 | 1 | 181.8*** | 97.3
8 | 10 | 189.6 ± 3.4*** | 10 | 190.9 ± 4.7 | 100.7 | 10 | 197.5 ± 3.5 | 104.2 | 10 | 189.4 ± 4.2 | 99.9 | 10 | 179.9 ± 2.2** | 94.9 | 1 | 177.3*** | 93.5
9 | 10 | 193.2 ± 4.2*** | 10 | 193.8 ± 4.8 | 100.3 | 10 | 200.8 ± 4.2 | 103.9 | 10 | 191.2 ± 4.2 | 99.0 | 10 | 180.2 ± 2.8*** | 93.3 | 1 | 182.4*** | 94.4
10 | 10 | 196.8 ± 3.6*** | 10 | 197.2 ± 4.9 | 100.2 | 10 | 205.1 ± 4.2 | 104.2 | 10 | 194.0 ± 4.4 | 98.6 | 10 | 182.6 ± 2.0*** | 92.8 | 1 | 183.2*** | 93.1
11 | 10 | 200.1 ± 4.4*** | 10 | 200.1 ± 4.9 | 100.0 | 10 | 205.8 ± 4.4 | 102.8 | 10 | 196.6 ± 4.0 | 98.3 | 10 | 184.4 ± 1.8*** | 92.2 | 1 | 182.9*** | 91.4
12 | 10 | 199.9 ± 4.3*** | 10 | 201.5 ± 5.1 | 100.8 | 10 | 207.3 ± 4.4 | 103.7 | 10 | 195.9 ± 4.4 | 98.0 | 10 | 184.0 ± 2.1*** | 92.0 | 1 | 187.9*** | 94.0
13 | 10 | 202.1 ± 3.8*** | 10 | 205.9 ± 5.8 | 101.9 | 10 | 210.6 ± 4.1 | 104.2 | 10 | 198.8 ± 4.2 | 98.4 | 10 | 186.1 ± 2.6*** | 92.1 | 1 | 190.1*** | 94.1
Mean for Weeks
1–13 | | 184.2 ± 2.2*** | | 182.9 ± 2.2 | 100.3 | | 185.7 ± 2.3 | 101.8 | | 181.2 ± 2.2 | 99.3 | | 172.3 ± 2.2** | 94.5 | | 134.6 ± 3.5*** | 73.8

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant exposure trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^d^ Mean weight as percentage of control.

Table D-3 Body Weights of Male Mice in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 22.3 ± 0.3 | 10 | 22.6 ± 0.4 | | 10 | 22.2 ± 0.3 | | 10 | 22.5 ± 0.3 | | 10 | 22.1 ± 0.4 | | 10 | 22.8 ± 0.3
1 | 10 | 22.9 ± 0.2*** | 10 | 23.0 ± 0.3 | 100.4 | 10 | 23.1 ± 0.2 | 100.9 | 10 | 23.1 ± 0.3 | 100.9 | 10 | 22.7 ± 0.4 | 99.1 | 10 | 22.0 ± 0.3*** | 96.1
2 | 10 | 23.1 ± 0.2*** | 10 | 23.8 ± 0.3 | 103.0 | 10 | 23.7 ± 0.4 | 102.6 | 10 | 23.6 ± 0.3 | 102.2 | 10 | 23.3 ± 0.4 | 100.9 | 10 | 22.7 ± 0.3 | 98.3
3 | 10 | 24.2 ± 0.3*** | 10 | 24.7 ± 0.3 | 102.1 | 10 | 24.8 ± 0.3 | 102.5 | 10 | 24.6 ± 0.3 | 101.7 | 10 | 24.2 ± 0.4 | 100.0 | 10 | 23.2 ± 0.3** | 95.9
4 | 10 | 25.0 ± 0.3*** | 10 | 25.5 ± 0.3 | 102.0 | 10 | 25.5 ± 0.3 | 102.0 | 10 | 25.0 ± 0.3 | 100.0 | 10 | 24.4 ± 0.5 | 97.6 | 10 | 23.7 ± 0.3*** | 94.8
5 | 10 | 25.8 ± 0.4*** | 10 | 25.9 ± 0.4 | 100.4 | 10 | 26.4 ± 0.3 | 102.3 | 10 | 25.7 ± 0.5 | 99.6 | 10 | 25.4 ± 0.3 | 98.4 | 10 | 24.3 ± 0.4** | 94.2
6 | 10 | 26.4 ± 0.4*** | 10 | 26.6 ± 0.3 | 100.8 | 10 | 26.9 ± 0.3 | 101.9 | 10 | 26.3 ± 0.4 | 99.6 | 10 | 26.0 ± 0.5 | 98.5 | 10 | 24.7 ± 0.4*** | 93.6
7 | 10 | 26.8 ± 0.4*** | 10 | 27.3 ± 0.3 | 101.9 | 10 | 27.3 ± 0.4 | 101.9 | 10 | 26.3 ± 0.5 | 98.1 | 10 | 26.2 ± 0.4 | 97.8 | 10 | 25.0 ± 0.4*** | 93.3
8 | 10 | 27.4 ± 0.5*** | 10 | 27.5 ± 0.3 | 100.4 | 10 | 27.1 ± 0.4 | 98.9 | 10 | 27.0 ± 0.5 | 98.5 | 10 | 26.8 ± 0.5 | 97.8 | 10 | 24.9 ± 0.3*** | 90.9
9 | 10 | 27.8 ± 0.7*** | 10 | 27.9 ± 0.6 | 100.4 | 10 | 28.3 ± 0.5 | 101.8 | 10 | 27.4 ± 0.5 | 98.6 | 10 | 27.1 ± 0.4 | 97.5 | 10 | 25.3 ± 0.3*** | 91.0
10 | 10 | 27.9 ± 0.5*** | 10 | 27.9 ± 0.3 | 100.0 | 10 | 28.2 ± 0.4 | 101.1 | 10 | 27.7 ± 0.6 | 99.3 | 10 | 27.0 ± 0.5 | 96.8 | 10 | 25.2 ± 0.4*** | 90.3
11 | 10 | 28.3 ± 0.6*** | 10 | 28.9 ± 0.3 | 102.1 | 10 | 29.1 ± 0.5 | 102.8 | 10 | 28.2 ± 0.6 | 99.6 | 10 | 27.3 ± 0.3 | 96.5 | 10 | 26.2 ± 0.3*** | 92.6
12 | 10 | 29.9 ± 0.7*** | 10 | 29.3 ± 0.5 | 98.0 | 10 | 29.1 ± 0.4 | 97.3 | 10 | 28.7 ± 0.6 | 96.0 | 10 | 28.4 ± 0.5 | 95.0 | 10 | 27.0 ± 0.5*** | 90.3
13 | 10 | 30.5 ± 0.7*** | 10 | 30.4 ± 0.5 | 99.7 | 10 | 30.6 ± 0.5 | 100.3 | 10 | 29.9 ± 0.7 | 98.0 | 10 | 29.3 ± 0.5 | 96.1 | 10 | 28.0 ± 0.4** | 91.8
Mean for Weeks
1–13 | | 26.7 ± 0.3*** | | 26.7 ± 0.3 | 100.0 | | 27.0 ± 0.3 | 101.1 | | 26.4 ± 0.3 | 98.9 | | 26.2 ± 0.3 | 98.1 | | 24.5 ± 0.3*** | 91.8

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant exposure trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.01 (**); p ≤ 0.001 (***).

^d^ Mean weight as percentage of control.

Table D-4 Body Weights of Female Mice in the Three-month Feed Study of Usnea Lichens

Week^a^ | 0 ppm | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 17.4 ± 0.3 | 10 | 17.0 ± 0.3 | | 10 | 16.9 ± 0.3 | | 10 | 17.7 ± 0.3 | | 10 | 17.7 ± 0.3 | | 10 | 17.2 ± 0.2
1 | 10 | 18.4 ± 0.2*** | 10 | 18.3 ± 0.2 | 99.5 | 10 | 18.1 ± 0.3 | 98.4 | 10 | 18.6 ± 0.3 | 101.1 | 10 | 18.5 ± 0.2 | 100.5 | 10 | 17.2 ± 0.3*** | 93.5
2 | 10 | 19.2 ± 0.3*** | 10 | 19.9 ± 0.2* | 103.6 | 10 | 19.2 ± 0.3 | 100.0 | 10 | 19.4 ± 0.3 | 101.0 | 10 | 19.7 ± 0.2 | 102.6 | 10 | 18.1 ± 0.2** | 94.3
3 | 10 | 20.0 ± 0.3*** | 10 | 20.8 ± 0.3** | 104.0 | 10 | 19.9 ± 0.3 | 99.5 | 10 | 20.3 ± 0.3 | 101.5 | 10 | 20.5 ± 0.2 | 102.5 | 10 | 18.4 ± 0.2*** | 92.0
4 | 10 | 20.7 ± 0.3*** | 10 | 21.3 ± 0.3 | 102.9 | 10 | 20.5 ± 0.4 | 99.0 | 10 | 21.0 ± 0.4 | 101.4 | 10 | 21.0 ± 0.3 | 101.4 | 9 | 18.9 ± 0.2*** | 91.3
5 | 10 | 21.6 ± 0.3*** | 10 | 22.1 ± 0.3 | 102.3 | 10 | 21.1 ± 0.3 | 97.7 | 10 | 21.4 ± 0.5 | 99.1 | 10 | 21.4 ± 0.3 | 99.1 | 9 | 19.1 ± 0.2*** | 88.4
6 | 10 | 22.1 ± 0.3*** | 10 | 22.6 ± 0.3 | 102.3 | 10 | 21.5 ± 0.3 | 97.3 | 10 | 21.8 ± 0.4 | 98.6 | 10 | 21.7 ± 0.2 | 98.2 | 9 | 19.5 ± 0.3*** | 88.2
7 | 10 | 22.8 ± 0.5*** | 10 | 23.1 ± 0.5 | 101.3 | 10 | 22.3 ± 0.5 | 97.8 | 10 | 22.6 ± 0.4 | 99.1 | 10 | 22.0 ± 0.3 | 96.5 | 9 | 19.6 ± 0.2*** | 86.0
8 | 10 | 23.3 ± 0.4*** | 10 | 23.1 ± 0.5 | 99.1 | 10 | 22.6 ± 0.5 | 97.0 | 10 | 22.9 ± 0.6 | 98.3 | 10 | 22.1 ± 0.2* | 94.8 | 9 | 20.0 ± 0.3*** | 85.8
9 | 9 | 23.4 ± 0.4*** | 10 | 23.3 ± 0.4 | 99.6 | 10 | 22.6 ± 0.5 | 96.6 | 10 | 22.6 ± 0.4 | 96.6 | 10 | 22.7 ± 0.2 | 97.0 | 9 | 20.3 ± 0.3*** | 86.8
10 | 9 | 22.8 ± 0.4*** | 10 | 23.3 ± 0.4 | 102.2 | 10 | 23.1 ± 0.4 | 101.3 | 10 | 23.1 ± 0.5 | 101.3 | 10 | 23.0 ± 0.2 | 100.9 | 9 | 20.4 ± 0.2*** | 89.5
11 | 9 | 23.3 ± 0.5*** | 10 | 23.9 ± 0.6 | 102.6 | 10 | 23.7 ± 0.6 | 101.7 | 10 | 23.5 ± 0.4 | 100.9 | 10 | 23.5 ± 0.2 | 100.9 | 9 | 20.7 ± 0.2*** | 88.8
12 | 9 | 24.2 ± 0.6*** | 10 | 24.4 ± 0.5 | 100.8 | 10 | 23.8 ± 0.6 | 98.3 | 10 | 24.4 ± 0.6 | 100.8 | 10 | 24.0 ± 0.4 | 99.2 | 9 | 20.8 ± 0.4*** | 86.0
13 | 9 | 24.9 ± 0.7*** | 10 | 24.9 ± 0.5 | 100.0 | 10 | 24.3 ± 0.5 | 97.6 | 10 | 24.8 ± 0.6 | 99.6 | 10 | 24.3 ± 0.4 | 97.6 | 9 | 21.7 ± 0.3*** | 87.1
Mean for Weeks
1–13 | | 22.0 ± 0.2*** | | 22.6 ± 0.2 | 102.7 | | 22.0 ± 0.2 | 100.0 | | 21.8 ± 0.2 | 99.1 | | 21.6 ± 0.2 | 98.2 | | 19.6 ± 0.2*** | 89.1

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant exposure trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^d^ Mean weight as percentage of control.