# Appendix C Hematology and Clinical Chemistry Data

Table C-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Male
Number of Animals | 10 | 10 | 10 | 10 | 10 | 8
Leukocyte Cell Count (10^3^/µL) | 6.45 ± 0.58 | 6.23 ± 0.63 | 8.20 ± 0.43 | 7.10 ± 0.60 | 6.76 ± 0.33 | 6.14 ± 0.69
Erythrocyte Cell Count (10^3^/µL) | 9.5 ± 0.12* | 9.32 ± 0.11 | 9.55 ± 0.07 | 9.43 ± 0.12 | 9.40 ± 0.09 | 8.38 ± 0.78*
Hemoglobin (g/dL) | 17.15 ± 0.11** | 17.00 ± 0.04 | 17.34 ± 0.07 | 17.21 ± 0.15 | 17.44 ± 0.14 | 15.3 ± 1.42*
Hematocrit (%) | 47.61 ± 0.66*** | 47.04 ± 0.50 | 47.96 ± 0.33 | 47.39 ± 0.60 | 47.89 ± 0.44 | 40.93 ± 3.91*^b^
Mean Cell Volume (µm^3^) | 50.1 ± 0.23** | 50.60 ± 0.22 | 50.30 ± 0.21 | 50.30 ± 0.15 | 51.00 ± 0.21 | 48.88 ± 0.64*
Mean Cell Hemoglobin (pg) | 18.04 ± 0.20 | 18.28 ± 0.21 | 18.15 ± 0.12 | 18.27 ± 0.14 | 18.53 ± 0.11 | 18.38 ± 0.12
Mean Cell Hemoglobin Concentration (g/dL) | 36.05 ± 0.39*** | 36.16 ± 0.39 | 36.18 ± 0.19 | 36.32 ± 0.23 | 36.39 ± 0.13 | 37.78 ± 0.36***
Platelet Count (10^3^/µL) | 514.4 ± 18.11*** | 525.80 ± 11.65 | 531.00 ± 19.87 | 542.80 ± 11.06 | 511.90 ± 44.41 | 260.8 ± 48.51***
Glucose (mg/dL) | 132.90 ± 4.66 | 136.90 ± 11.32 | 143.40 ± 9.04 | 137.00 ± 8.81 | 122.20 ± 5.50 | 120.60 ± 17.80^b^
Creatinine (mg/dL) | 0.47 ± 0.02 | 0.49 ± 0.01 | 0.52 ± 0.02 | 0.51 ± 0.02 | 0.54 ± 0.03 | 0.50 ± 0.04*^c^
Blood Urea Nitrogen (mg/dL) | 14.2 ± 0.39*** | 13.60 ± 0.40 | 15.20 ± 0.44 | 14.80 ± 0.39 | 16.00 ± 0.52 | 28.00 ± 3.74***^c^
Alanine Aminotransferase (U/L) | 44.1 ± 2.09*** | 45.10 ± 1.59 | 42.50 ± 1.60 | 44.90 ± 1.29 | 48.30 ± 2.91 | 83.3 ± 8.08***^b^
Protein Concentration (g/dL) | 7.67 ± 0.11*** | 7.62 ± 0.10 | 7.49 ± 0.18 | 7.68 ± 0.09 | 7.67 ± 0.15 | 6.30 ± 0.48***^c^
Albumin (g/dL) | 4.13 ± 0.04*** | 4.10 ± 0.03 | 4.08 ± 0.05 | 4.22 ± 0.04 | 4.11 ± 0.06 | 3.40 ± 0.23***^c^
Serum Phosphate Concentration (mg/dL) | 5.72 ± 0.17* | 5.43 ± 0.20 | 5.85 ± 0.14 | 6.04 ± 0.24 | 5.68 ± 0.22 | 6.15 ± 0.37^c^
Alkaline Phosphatase (U/L) | 119.80 ± 3.68 | 112.50 ± 5.03 | 108.30 ± 3.84 | 110.70 ± 2.89 | 106.10 ± 5.01 | 137.00 ± 18.33^c^
Creatine Kinase (U/L) | 304.9 ± 44.52* | 303.00 ± 61.80 | 362.70 ± 77.35 | 381.20 ± 107.01 | 485.60 ± 188.45 | 1,090 ± 814.20**^c^
Female
Number of Animals | 10 | 9 | 10 | 10 | 10 | 7
Leukocyte Cell Count (10^3^/µL) | 5.17 ± 0.35* | 4.48 ± 0.25 | 4.52 ± 0.53 | 4.42 ± 0.30 | 5.03 ± 0.48 | 5.91 ± 0.73***
Erythrocyte Cell Count (10^3^/µL) | 8.89 ± 0.10*** | 8.72 ± 0.11 | 8.83 ± 0.11 | 8.67 ± 0.12 | 8.38 ± 0.10 | 7.59 ± 0.60
Hemoglobin (g/dL) | 17.07 ± 0.17*** | 16.96 ± 0.15 | 16.98 ± 0.11 | 16.95 ± 0.26 | 16.73 ± 0.16 | 14.37 ± 1.04***
Hematocrit (%) | 46.62 ± 0.53*** | 45.94 ± 0.70 | 46.69 ± 0.57 | 45.81 ± 0.62 | 44.91 ± 0.56 | 37.94 ± 3.09***
Mean Cell Volume (µm^3^) | 52.4 ± 0.16*** | 52.56 ± 0.18 | 52.80 ± 0.13 | 52.90 ± 0.18 | 53.50 ± 0.17 | 49.86 ± 0.59***
Mean Cell Hemoglobin (pg) | 19.18 ± 0.12 | 19.48 ± 0.27 | 19.23 ± 0.13 | 19.54 ± 0.07 | 19.95 ± 0.09** | 19.04 ± 0.30
Mean Cell Hemoglobin Concentration (g/dL) | 36.57 ± 0.21*** | 36.98 ± 0.59 | 36.40 ± 0.24 | 37.00 ± 0.13 | 37.26 ± 0.16 | 38.54 ± 0.60***
Platelet Count (10^3^/µL) | 545.90 ± 41.16*** | 542.33 ± 47.92 | 609.00 ± 19.28 | 569.70 ± 32.85 | 587.90 ± 17.80 | 208.43 ± 54.92***
Glucose (mg/dL) | 124.6 ± 5.24*** | 114.67 ± 5.54 | 118.20 ± 5.86 | 105.60 ± 5.23 | 112.00 ± 2.91 | 150.12 ± 12.02*^d^
Creatinine (mg/dL) | 0.43 ± 0.02** | 0.50 ± 0.02 | 0.49 ± 0.01 | 0.49 ± 0.01 | 0.57 ± 0.02*** | 0.53 ± 0.03**^e^
Blood Urea Nitrogen (mg/dL) | 16.20 ± 0.33*** | 16.22 ± 0.55 | 17.20 ± 0.44 | 17.00 ± 0.75 | 17.80 ± 0.47 | 24.00 ± 2.08***^e^
Alanine Aminotransferase (U/L) | 38.70 ± 1.40*** | 41.22 ± 1.91 | 41.90 ± 1.68 | 43.80 ± 1.65 | 46.50 ± 1.21 | 81.88 ± 7.14***^d^
Protein Concentration (g/dL) | 7.18 ± 0.13 | 7.18 ± 0.11 | 7.35 ± 0.11 | 7.25 ± 0.14 | 7.30 ± 0.14 | 6.20 ± 0.67**^e^
Albumin (g/dL) | 4.04 ± 0.06*** | 4.03 ± 0.04 | 4.10 ± 0.03 | 4.03 ± 0.04 | 4.04 ± 0.04 | 3.50 ± 0.36**^e^
Serum Phosphate Concentration (mg/dL) | 5.90 ± 0.34** | 5.26 ± 0.35 | 5.45 ± 0.24 | 5.70 ± 0.28 | 6.27 ± 0.15 | 7.00 ± 0.53^e^
Alkaline Phosphatase (U/L) | 71.79 ± 8.06*** | 83.00 ± 4.15 | 76.00 ± 3.34 | 78.70 ± 2.87 | 73.70 ± 2.50 | 227.16 ± 24.34***^e^
Creatine Kinase (U/L) | 264.80 ± 54.75 | 253.56 ± 42.18 | 195.90 ± 29.99 | 282.50 ± 47.22 | 200.90 ± 22.76 | 217.67 ± 60.92^e^

^a^ Values are given as means ± standard error of the mean. For the control (0 ppm) group, asterisks represent significance for linear trend and for the exposed groups, asterisks represent significance in comparison to the control group using two-tailed Dunnett tests: p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^b^ Number of animals (n) = 10.

^c^ n = 4.

^d^ n = 8.

^e^ n = 3.

Table C-2 Hematology and Clinical Chemistry Data for Mice in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Male
Number of Animals | 10 | 10 | 10 | 10 | 10 | 10
Leukocyte Cell Count (10^3^/µL) | 1.39 ± 0.28 | 0.80 ± 0.10 | 1.21 ± 0.21 | 1.13 ± 0.24 | 2.09 ± 0.64 | 1.33 ± 0.21
Erythrocyte Cell Count (10^3^/µL) | 10.00 ± 0.14 | 9.71 ± 0.22 | 10.04 ± 0.18 | 10.13 ± 0.16 | 9.89 ± 0.22 | 9.86 ± 0.16
Hemoglobin (g/dL) | 16.11 ± 0.21 | 16.23 ± 0.11 | 16.26 ± 0.19 | 16.47 ± 0.10 | 16.13 ± 0.31 | 15.74 ± 0.27
Hematocrit (%) | 48.98 ± 0.68 | 47.46 ± 1.15 | 48.87 ± 0.83 | 49.69 ± 0.83 | 48.57 ± 0.91 | 47.84 ± 0.66
Mean Cell Volume (µm^3^) | 48.90 ± 0.18 | 48.80 ± 0.20 | 48.60 ± 0.22 | 49.00 ± 0.15 | 49.40 ± 0.31 | 48.50 ± 0.27
Mean Cell Hemoglobin (pg) | 16.12 ± 0.07 | 16.80 ± 0.41 | 16.23 ± 0.12 | 16.28 ± 0.22 | 16.34 ± 0.07 | 15.95 ± 0.08
Mean Cell Hemoglobin Concentration (g/dL) | 32.90 ± 0.09 | 34.39 ± 0.92* | 33.34 ± 0.28 | 33.18 ± 0.46 | 33.20 ± 0.10 | 32.89 ± 0.17
Platelet Count (10^3^/µL) | 828.50 ± 25.76 | 814.10 ± 18.53 | 833.90 ± 22.34 | 869.60 ± 25.17 | 870.10 ± 33.94 | 880.70 ± 29.57
Glucose (mg/dL) | 161.8 ± 10.05*** | 144.00 ± 5.64 | 158.50 ± 9.51 | 134.60 ± 5.15 | 171.40 ± 14.92 | 200.1 ± 10.83*^b^
Creatinine (mg/dL) | 0.30 ± 0.01 | 0.32 ± 0.01 | 0.34 ± 0.02 | 0.35 ± 0.02 | 0.36 ± 0.02 | 0.43 ± 0.02***
Blood Urea Nitrogen (mg/dL) | 24.60 ± 0.70 | 22.00 ± 0.63 | 24.60 ± 1.00 | 24.50 ± 0.76 | 25.00 ± 1.64 | 26.60 ± 1.27
Alanine Aminotransferase (U/L) | 32.50 ± 3.54 | 27.50 ± 0.82 | 33.10 ± 2.24 | 34.50 ± 1.40 | 70.80 ± 30.65 | 32.78 ± 1.20^b^
Protein Concentration (g/dL) | 5.94 ± 0.04 | 6.02 ± 0.07 | 6.10 ± 0.10 | 6.26 ± 0.10* | 5.84 ± 0.06 | 6.07 ± 0.07^b^
Serum Albumin Concentration (g/dL) | 3.40 ± 0.03 | 3.43 ± 0.04 | 3.50 ± 0.05 | 3.56 ± 0.06 | 3.31 ± 0.04^b^ | 3.43 ± 0.04^b^
Serum Phosphate Concentration (mg/dL) | 8.02 ± 0.38 | 7.47 ± 0.34 | 7.21 ± 0.41 | 7.53 ± 0.42 | 8.14 ± 0.19 | 7.81 ± 0.23^b^
Alkaline Phosphatase (U/L) | 75.6 ± 3.90*** | 76.40 ± 3.68 | 80.70 ± 4.88 | 91.60 ± 8.22 | 72.70 ± 2.56 | 126.2 ± 6.18***^b^
Creatine Kinase (U/L) | 354.10 ± 71.01 | 419.10 ± 137.64 | 352.00 ± 51.35 | 358.50 ± 66.59 | 999.90 ± 626.96 | 328.00 ± 87.24^b^
Female
Number of Animals | 10 | 10 | 10 | 10 | 10 | 9
Leukocyte Cell Count (10^3^/µL) | 2.08 ± 0.57 | 2.59 ± 0.47 | 2.38 ± 0.40 | 1.81 ± 0.26 | 2.30 ± 0.35 | 2.44 ± 0.30
Erythrocyte Cell Count (10^3^/µL) | 10.62 ± 0.13 | 10.51 ± 0.10 | 10.58 ± 0.17 | 10.48 ± 0.12 | 10.39 ± 0.14 | 10.34 ± 0.09
Hemoglobin (g/dL) | 17.00 ± 0.15 | 17.23 ± 0.14 | 17.14 ± 0.34 | 17.19 ± 0.24 | 17.11 ± 0.17 | 17.02 ± 0.18
Hematocrit (%) | 50.95 ± 0.56 | 51.13 ± 0.46 | 51.56 ± 0.89 | 51.13 ± 0.62 | 51.04 ± 0.60 | 51.13 ± 0.37
Mean Cell Volume (µm^3^) | 48.0 ± 0.33*** | 48.70 ± 0.15 | 48.70 ± 0.15 | 49.00 ± 0.00 | 49.10 ± 0.23 | 49.56 ± 0.18***
Mean Cell Hemoglobin (pg) | 16.04 ± 0.20 | 16.42 ± 0.10 | 16.19 ± 0.09 | 16.38 ± 0.05 | 16.49 ± 0.09 | 16.46 ± 0.10
Mean Cell Hemoglobin Concentration (g/dL) | 33.36 ± 0.25 | 33.74 ± 0.18 | 33.21 ± 0.17 | 33.62 ± 0.09 | 33.54 ± 0.13 | 33.31 ± 0.22
Platelet Count (10^3^/µL) | 848.3 ± 86.90* | 740.70 ± 30.31 | 769.80 ± 36.10 | 791.00 ± 11.96 | 800.90 ± 18.58 | 822.44 ± 24.03
Glucose (mg/dL) | 157.70 ± 19.07 | 171.50 ± 11.26 | 188.30 ± 8.24 | 155.50 ± 7.69 | 182.00 ± 9.44 | 177.00 ± 5.36
Creatinine (mg/dL) | 0.34 ± 0.03*** | 0.30 ± 0.00 | 0.29 ± 0.02 | 0.33 ± 0.02 | 0.38 ± 0.02* | 0.44 ± 0.02***
Blood Urea Nitrogen (mg/dL) | 55.10 ± 34.89 | 21.70 ± 1.22 | 21.44 ± 1.45^b^ | 20.00 ± 0.94 | 21.67 ± 0.91^b^ | 22.56 ± 1.53
Alanine Aminotransferase (U/L) | 47.22 ± 9.64^b^ | 27.80 ± 1.60 | 30.33 ± 2.09^b^ | 32.40 ± 2.97 | 34.00 ± 5.57^b^ | 38.00 ± 6.39
Protein Concentration (g/dL) | 6.12 ± 0.22** | 6.32 ± 0.06 | 6.12 ± 0.08^b^ | 6.31 ± 0.06 | 6.52 ± 0.11^b^ | 6.58 ± 0.11^c^
Albumin (g/dL) | 3.55 ± 0.22^c^ | 3.69 ± 0.04^b^ | 3.60 ± 0.03 | 3.54 ± 0.18 | 3.70 ± 0.07^b^ | 3.84 ± 0.07
Serum Phosphate Concentration (mg/dL) | 8.65 ± 1.10 | 7.57 ± 0.35 | 7.56 ± 0.24 | 7.51 ± 0.30 | 7.09 ± 0.35 | 7.50 ± 0.42^c^
Alkaline Phosphatase (U/L) | 121.6 ± 6.54** | 128.70 ± 5.37 | 122.40 ± 6.77 | 118.90 ± 7.57 | 112.75 ± 6.16^c^ | 157.13 ± 6.81^c^
Creatine Kinase (U/L) | 733.00 ± 210.55 | 312.80 ± 47.39 | 354.60 ± 90.24 | 459.00 ± 87.50 | 372.50 ± 67.72^c^ | 331.88 ± 79.82^c^

^a^ Values are given as means ± standard error of the mean. Under the control (0 ppm) group, asterisks represent significance for linear trend and for the exposed groups, asterisks represent significance in comparison to the control group using two-tailed Dunnett tests; p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^b^ Number of animals (n) = 9.

^c^ n = 8.