# Appendix B Genetic Toxicology Studies

## B.1 Background

(+)-Usnic acid has been tested for genotoxicity in several in vitro systems. It showed no mutagenicity in tested strains including TA98 and TA100 with or without S9 addition at a highest dose of 200 µg per plate.^28^ NTP studies confirmed that (+)-usnic acid was negative in Ames tests with S. typhimurium strains TA98 and TA100 and E. coli strain WP2 uvrA (pkM101), with and without the addition of rat liver S9.^94^ (+)-Usnic acid was evaluated for genotoxicity in human lymphocytes in vitro using the cytokinesis-blocked micronucleus (CBMN) assay.^72^ Although the number of micronuclei was higher in the lymphocytes treated with (+)-usnic acid in comparison with control lymphocytes, the induction was not significant statistically. The authors concluded that (+)-usnic acid was nongenotoxic as shown by the absence of significant micronucleus induction in human lymphocytes. Oral administration of a single dose of either 100 or 200 mg/kg usnic acid caused a slight increase in micronucleated erythrocytes in the mice 24 and 48 hours after treatment, which did not reach statistical significance and returned to control levels by 72 hours.^73^

The objective of this genetic toxicity evaluation was to determine whether in vivo exposure to Usnea lichens, containing (+/−)-usnic acid, would significantly increase micronuclei formation in peripheral blood from mice that were exposed to Usnea lichens for the 2-week acute toxicity studies that were run in conjunction with this 3-month study.

## B.2 Methods

Peripheral blood was collected at sacrifice from B6C3F1/Nctr mice evaluated for the 2-week acute toxicity studies (Appendix J), and aliquots were diluted with anticoagulant, fixed in cold (−80°C) methanol, and stored at −85°C. The fixed blood samples were shipped to Litron Laboratories (Rochester, NY) on dry ice for analysis. Micronucleated cells were identified and quantified using a MicroFlow PLUS mouse kit from Litron Laboratories.^95,96^ Briefly, reticulocytes were identified by fluorescein isothiocyanate-labeled antibodies against the CD71 mouse surface antigen, platelets were identified by phycoerythrin-labeled antibodies against CD61 antigen, and DNA, including micronuclei, was stained with propidium iodide. Data provided by Litron was compiled in the form of sorted spreadsheets of differences in reticulocyte micronucleus frequency between dose groups, and as audited study reports that have been added to the Study Archive. The spreadsheet data were then analyzed at NCTR in SAS (version 9.1, TS level 1M3) to produce means, standard error values, and significant differences between dose groups via a Dunnett test evaluation and a linear trend test run under the SAS General Linear Models program.

## B.3 Results

The micronucleus frequencies for male and female B6C3F1/Nctr mice exposed to Usnea lichens containing (+/−)-usnic acid in feed for 14 days are shown in Table B-1. In males, (+/−)-usnic acid exposure did not significantly change the percentage of total reticulocytes in the samples (% RET) or the percentage of micronucleated normochromatic erythrocytes (% NCE) in the samples but did significantly increase the percentage of micronucleated reticulocytes (% micronucleated RET) in the 600 ppm group with a significant dose trend. However, these increases were relatively small. In female B6C3F1/Nctr mice exposed to Usnea lichens containing (+/−)-usnic acid, there was a large statistically significant decrease in the % RET and a significant increase in % micronucleated RET in the 600 ppm group. The increase in % micronucleated RET was relatively small. The decrease in % RET at the high exposure level could reflect an anemic toxic response.

Table B-1 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in Mice in the Two-week Feed Study of Usnea Lichens

| % RET | % Micronucleated NCE | % Micronucleated RET
Male
Vehicle Control | 4^a^ | 4 | 4
Mean ± standard error | 1.9 ± 0.07 | 0.16 ± 0.006 | 0.28 ± 0.005
Trend test p value | p = 0.64^b^ | p = 0.60 | p ≤ 0.001
30 ppm | 4 | 4 | 4
Mean ± standard error | 3.3 ± 0.25 | 0.15 ± 0.000 | 0.27 ± 0.021
Dunnett’s test p value | p = 0.93 | p = 0.22 | p = 1.00
60 ppm | 3 | 3 | 3
Mean ± standard error | 2.16 ± 0.42 | 0.13 ± 0.003 | 0.27 ± 0.015
Dunnett’s test p value | p = 0.98 | p = 0.07 | p = 1.00
180 ppm | 4 | 4 | 4
Mean ± standard error | 2.2 ± 0.25 | 0.16 ± 0.009 | 0.30 ± 0.011
Dunnett’s test p value | p = 0.95 | p = 0.75 | p = 0.97
600 ppm | 4 | 4 | 4
Mean ± standard error | 1.8 ± 2.2 | 0.15 ± 0.005 | 0.67 ± 0.075
Dunnett’s test p value | p = 1.0 | p = 0.75 | p ≤ 0.001
Female
Vehicle Control | 4 | 4 | 4
Mean ± standard error | 2.4 ± 0.31 | 0.12 ± 0.008 | 0.22 ± 0.031
Trend test p value | p ≤ 0.001 | p = 0.53 | p ≤ 0.001
30 ppm | 4 | 4 | 4
Mean ± standard error | 2.5 ± 0.32 | 0.11 ± 0.003 | 0.20 ± 0.023
Dunnett’s test p value | p = 1.0 | p = 1.0 | p = 0.93
60 ppm | 3 | 3 | 3
Mean ± standard error | 1.8 ± 0.25 | 0.11 ± 0.010 | 0.24 ± 0.046
Dunnett’s test p value | p = 0.21 | p = 0.99 | p = 0.98
180 ppm | 4 | 4 | 4
Mean ± standard error | 2.0 ± 0.12 | 0.13 ± 0.004 | 0.28 ± 0.014
Dunnett’s test p value | p = 0.53 | p = 0.12 | p = 0.46
600 ppm | 4 | 4 | 4
Mean ± standard error | 0.61 ± 0.05 | 0.11 ± 0.003 | 0.40 ± 0.022
Dunnett’s test p value | p ≤ 0.001 | p = 0.92 | p = 0.001

RET = reticulocytes expressed as percentages of total red blood cells; NCE = normochromatic erythrocytes.

^a^ Number examined.

^b^ p values listed under the control group values denote trend test significance, and those beneath the dosed group values denote significance of Dunnett test pairwise comparisons between the feed controls and that dosed group. Two-tailed Dunnett tests were used.