# Appendix A Summary and Statistical Analysis of Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths
Moribund sacrifice | 0 | 0 | 0 | 0 | 0 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 0
Alimentary System
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Cyst | 0 | 0 | 0 | 1 (10%) | 0 | 0
Deformity | 0 | 1 (10%) | 0 | 0 | 0 | 0
Inflammation, chronic active | 5 (50%) | 1 (10%) | 3 (30%) | 4 (40%) | 3 (30%)
Necrosis | 0 | 1 (10%) | 0 | 0 | 0 | 0
Tension lipidosis | 0 | 0 | 0 | 0 | 1 (10%) | 0
Hepatocellular degeneration | 1 (10%) | (0) | 1 (10%) | 6 (60%) | 10 (100%) | 10 (100%)
Pancreas | (10) | (0) | (0) | (0) | (10) | (10)
Infiltration cellular, lymphocyte | 0 | –^b^ | – | – | – | 1 (10%)
Vacuolization cytoplasmic | 1 (10%) | – | – | – | – | 0
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (10) | (10)
Cardiomyopathy | 7 (70%) | – | – | – | 7 (70%) | (0)
Myocardium, vacuolization cytoplasmic | (0) | – | – | – | (0) | 1 (10%)
Endocrine System
Adrenal Cortex | (10) | (0) | (0) | (0) | (10) | (10)
Vacuolization cytoplasmic | 4 (40%) | – | – | – | 2 (20%) | 10 (100%)
Thyroid Gland | (10) | (0) | (0) | (0) | (10) | (10)
Ectopic thymus | 1 (10%) | – | – | – | 0 | 1 (10%)
General Body System
Tissue NOS | (1) | (0) | (0) | (0) | (0) | (0)
Mediastinum, hemorrhage | 1 (100%) | – | – | – | – | –
Genital System
Epididymis | (10) | (0) | (0) | (0) | (10) | (10)
Exfoliated germ cell | 0 | – | – | – | 0 | 10 (100%)
Hypospermia | | | | | | 10 (100%)
Preputial Gland | (10) | (0) | (0) | (0) | (10) | (10)
Infiltration cellular, lymphocyte | 0 | – | – | – | 1 (10%) | 0
Inflammation, suppurative | 2 (20%) | – | – | – | 4 (40%) | 8 (80%)
Inflammation, chronic active | 3 (30%) | – | – | – | 0 | 0
Duct, ectasia | 0 | – | – | – | 2 (20%) | 0
Prostate | (10) | (0) | (0) | (0) | (10) | (10)
Atrophy | 0 | – | – | – | 0 | 10 (100%)
Seminal Vesicle | (10) | (0) | (0) | (0) | (10) | (10)
Atrophy | 0 | – | – | – | 0 | 10 (100%)
Testes | (10) | (0) | (0) | (0) | (10) | (10)
Seminiferous tubule, degeneration | 0 | – | – | – | 0 | 10 (100%)
Hematopoietic System
Bone Marrow | (10) | (0) | (0) | (0) | (10) | (10)
Congestion | 0 | – | – | – | 0 | 1 (10%)
Hypocellularity | 0 | – | – | – | 0 | 10 (100%)
Lymph Node, Lumbar | (0) | (0) | (0) | (0) | (0) | (1)
Hyperplasia, lymphoid | – | – | – | – | – | 1 (100%)
Lymph Node, Mandibular | (10) | (0) | (0) | (0) | (10) | (10)
Hyperplasia, lymphoid | 0 | – | – | – | 1 (10%) | 2 (20%)
Lymph Node, Mesenteric | (10) | (0) | (0) | (0) | (10) | (10)
Hyperplasia, lymphoid | 2 (20%) | – | – | – | 3 (30%) | 0
Thymus | (10) | (0) | (0) | (0) | (10) | (10)
Atrophy | 0 | – | – | – | 0 | 9 (90%)
Cyst | 0 | – | – | – | 0 | 1 (10%)
Integumentary System
Mammary Gland | (10) | (0) | (0) | (0) | (10) | (10)
Atrophy | 0 | – | – | – | 0 | 9 (90%)
Musculoskeletal System
None
Nervous System
Brain, Cerebrum | (10) | (0) | (0) | (0) | (10) | (10)
Gliosis | 1 (10%) | – | – | – | – | 0
Mineralization | 1 (10%) | – | – | – | 0 | 0
Respiratory System
Lung | (10) | (0) | (0) | (0) | (10) | (10)
Congestion | 0 | – | – | – | 0 | 1 (10%)
Hemorrhage | 1 (10%) | – | – | – | 0 | 0
Infiltration cellular, histiocyte | 0 | – | – | – | 0 | 1 (10%)
Alveolar epithelium, hyperplasia | 0 | – | – | – | 1 (10%) | 0
Nose | (10) | (0) | (0) | (0) | (10) | (10)
Malformation | 0 | – | – | – | 0 | 1 (10%)
Special Senses System
Harderian Gland | (10) | (0) | (0) | (0) | (10) | (10)
Infiltration cellular, lymphocyte | 0 | – | – | – | 1 (10%) | 0
Urinary System
Kidney | (10) | (0) | (0) | (0) | (10) | (10)
Casts protein | 0 | – | – | – | 2 (20%) | 0
Hyaline droplet | 1 (10%) | – | – | – | 0 | 0
Hydronephrosis | 1 (10%) | – | – | – | 0 | 2 (20%)
Mineralization | 1 (10%) | – | – | – | 0 | 0
Nephropathy | 3 (30%) | – | – | – | 4 (40%) | 5 (50%)
Urinary bladder | (10) | (0) | (0) | (0) | (10) | (10)
Lumen, dilatation | 0 | – | – | – | 0 | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-2 Statistical Analysis of Nonneoplastic Lesions in Male Rats in the Three-month Feed Study of Usnea Lichens

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Liver
Hepatocellular Degeneration
Overall rate^a^ | 1/10 (10.0%) | 0/10 (0.0%) | 1/10 (10.0%) | 6/10 (60.0%) | 10/10 (100.0%) | 10/10 (100.0%)
Terminal rate^b^ | 1/10 (10.0%) | 0/10 (0.0%) | 1/10 (10.0%) | 6/10 (60.0%) | 10/10 (100.0%) | –^c^
First incidence (days)^d^ | 90 (T) | – | 90 (T) | 90 (T) | 90 (T) | 27
CAFÉ p value^e^ | p ≤ 0.001 | p = 0.500N | p = 0.763 | p = 0.029 | p ≤ 0.001 | p ≤ 0.001
Average severity^f^ | 1.0 | – | 2.0 | 1.2 | 1.8 | 3.7
Inflammation
Overall rate | 5/10 (50.0%) | 1/10 (10.0%) | 3/10 (30.0%) | 4/10 (40.0%) | 3/10 (30.0%) | 0/10 (0.0%)
Terminal rate | 5/10 (50.0%) | 1/10 (10.0%) | 3/10 (30.0%) | 4/10 (40.0%) | 3/10 (30.0%) | –
First incidence (days) | 90 (T) | 90 (T) | 90 (T) | 90 (T) | 90 (T) | –
CAFÉ p value | p = 0.025N | p = 0.070N | p = 0.325N | p = 0.500N | p = 0.325N | p = 0.016N
Average severity | 1.0 | 2.0 | 1.0 | 1.0 | 1.0 | –
Heart
Cardiomyopathy
Overall rate | 7/10 (70.0%) | – | – | – | 7/10 (70.0%) | 0/10 (0.0%)
Terminal rate | 7/10 (70.0%) | – | – | – | 7/10 (70.0%) | –
First incidence (days) | 90 (T) | – | – | – | 90 (T) | –
CAFÉ p value | p = 0.002N | – | – | – | p = 0.686 | p = 0.002N
Average severity | 1.3 | – | – | – | 1.0 | –
Adrenal Cortex
Vacuolization Cytoplasmic
Overall rate | 4/10 (40.0%) | – | – | – | 2/10 (20.0%) | 10/10 (100.0%)
Terminal rate | 4/10 (40.0%) | – | – | – | 2/10 (20.0%) | 10/10 (100.0%)
First incidence (days) | 90 (T) | – | – | – | 90 (T) | 27
CAFÉ p value | p = 0.007 | – | – | – | p = 0.314N | p = 0.005
Average severity | 1.5 | – | – | – | 1.5 | 4.0
Epididymis
Hypospermia
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 27
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 4.0
Exfoliated Germ Cell
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 27
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 3.1
Preputial Gland
Chronic Active Inflammation
Overall rate | 3/10 (30.0%) | – | – | – | 0/10 (0.0%) | 0/10 (0.0%)
Terminal rate | 3/10 (30.0%) | – | – | – | 0/10 (0.0%) | 0/10 (0.0%)
First incidence (days) | 90 (T) | – | – | – | – | –
CAFÉ p value | p = 0.030N | – | – | – | p = 0.105N | p = 0.105N
Average severity | 2.3 | – | – | – | – | –
Suppurative Inflammation
Overall rate | 2/10 (20.0%) | – | – | – | 4/10 (40.0%) | 8/10 (80.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | 4/10 (40.0%) | –
First incidence (days) | 90 (T) | – | – | – | 90 (T) | 27
CAFÉ p value | p = 0.007 | – | – | – | p = 0.314 | p ≤ 0.012
Average severity | 1.5 | – | – | – | 2.0 | 3.0
Duct Ectasia
Overall rate | 0/10 (0.0%) | – | – | – | 2/10 (20.0%) | 0/10 (0.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 2/10 (20.0%) | –
First incidence (days) | – | – | – | – | 90 (T) | –
CAFÉ p value | p = 0.667 | – | – | – | p = 0.237 | –
Average severity | – | – | – | – | 2.5 | –
Prostate
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 27
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 4.0
Seminal Vesicle
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 27
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 4.0
Testes
Seminiferous Tubule Degeneration
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 27
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 4.0
Bone Marrow
Hypocellularity
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 27
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 3.6
Mesenteric Lymph Node
Hyperplasia
Overall rate | 2/10 (20.0%) | – | – | – | 3/10 (30.0%) | 0/10 (0.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | 3/10 (30.0%) | –
First incidence (days) | 90 (T) | – | – | – | 90 (T) | –
CAFÉ p value | p = 0.191N | – | – | – | p = 0.500 | p = 0.237N
Average severity | 2.0 | – | – | – | 2.0 | –
Mandibular Lymph Node
Hyperplasia
Overall rate | 0/10 (0.0%) | – | – | – | 1/10 (10.0%) | 2/10 (20.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 1/10 (10.0%) | –
First incidence (days) | – | – | – | – | 90 (T) | 27
CAFÉ p value | p = 0.140 | – | – | – | p = 0.500 | p = 0.237
Average severity | – | – | – | – | 2.0 | 1.5
Thymus
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 9/10 (90.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 27
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 3.8
Mammary Gland
Atrophy
Overall rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 9/10 (90.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | – | – | – | – | – | 30
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | – | – | – | – | – | 2.3
Kidney
Casts Protein
Overall rate | 0/10 (0.0%) | – | – | – | 2/10 (20.0%) | 0/10 (0.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | 2/10 (20.0%) | –
First incidence (days) | – | – | – | – | 90 (T) | –
CAFÉ p value | p = 0.667 | – | – | – | p = 0.237 | –
Average severity | – | – | – | – | 1.0 | –
Hydronephrosis
Overall rate | 1/10 (10.0%) | – | – | – | 0/10 (0.0%) | 2/10 (20.0%)
Terminal rate | 1/10 (10.0%) | – | – | – | 0/10 (0.0%) | –
First incidence (days) | 90 (T) | – | – | – | – | 27
CAFÉ p value | p = 0.362 | – | – | – | p = 0.500N | p = 0.500
Average severity | 2.0 | – | – | – | – | 2.0
Nephropathy
Overall rate | 3/10 (30.0%) | – | – | – | 4/10 (40.0%) | 5/10 (50.0%)
Terminal rate | 3/10 (30.0%) | – | – | – | 4/10 (40.0%) | –
First incidence (days) | 90 (T) | – | – | – | 90 (T) | 30
CAFÉ p value | p = 0.251 | – | – | – | p = 0.500 | p = 0.325
Average severity | 1.0 | – | – | – | 1.0 | 1.0

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Observed incidence at terminal sacrifice.

^c^ Indicates no data were collected.

^d^ Time to first lesion in days. T indicates terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths
Moribund sacrifice | 0 | 0 | 0 | 0 | 0 | 8
Natural death | 0 | 0 | 0 | 0 | 0 | 1
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 1
Alimentary System
Intestine Small, Ileum | (10) | (0) | (0) | (0) | (10) | (9)
Hyperplasia, lymphoid | 1 (10%) | –^b^ | – | – | 1 (10%) | 0
Liver | (10) | (0) | (0) | (0) | (10) | (10)
Hepatocellular degeneration | 0 | – | – | – | 0 | 10 (100%)
Pancreas | (10) | (0) | (0) | (0) | (10) | (10)
Vacuolization cytoplasmic | 0 | – | – | – | 0 | 1 (10%)
Acinus, degeneration | 0 | – | – | – | 1 (10%) | 0
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (10) | (10)
Cardiomyopathy | 3 (30%) | – | – | – | 1 (10%) | 1 (10%)
Endocrine System
Adrenal Cortex | (10) | (0) | (0) | (0) | (10) | (9)
Vacuolization cytoplasmic | 0 | – | – | – | 0 | 8 (89%)
Pituitary Gland | (10) | (0) | (0) | (0) | (10) | (9)
Pars distalis, cyst | 0 | – | – | – | 2 (20%) | 0
Thyroid Gland | (10) | (0) | (0) | (0) | (10) | (9)
Cyst, squamous | 0 | – | – | – | 1 (10%) | 0
Ectopic thymus | 1 (10%) | – | – | – | 2 (20%) | 1 (11%)
General Body System
None
Genital System
Clitoral Gland | (10) | (0) | (0) | (0) | (10) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | – | – | – | 0 | 2 (20%)
Inflammation, suppurative | 4 (40%) | – | – | – | 1 (10%) | 4 (40%)
Inflammation, chronic active | 2 (20%) | – | – | – | 0 | 0
Duct, ectasia | 1 (10%) | – | – | – | 0 | 1 (10%)
Uterus | (10) | (0) | (0) | (0) | (10) | (9)
Lumen, dilatation | 2 (20%) | – | – | – | 3 (30%) | 1 (11%)
Hematopoietic System
Bone Marrow | (10) | (0) | (0) | (0) | (10) | (9)
Hypocellularity | 0 | – | – | – | 0 | 8 (89%)
Lymph Node, Lumbar | (0) | (0) | (0) | (0) | (0) | (1)
Hyperplasia, lymphoid | – | – | – | – | – | 1 (100%)
Lymph Node, Mandibular | (10) | (0) | (0) | (0) | (10) | (9)
Hyperplasia, lymphoid | 2 (20%) | – | – | – | 0 | 0
Lymph Node, Mesenteric | (10) | (0) | (0) | (0) | (10) | (9)
Hyperplasia, lymphoid | 4 (40%) | – | – | – | 4 (40%) | 0
Thymus | (10) | (0) | (0) | (0) | (10) | (10)
Atrophy | 0 | – | – | – | 0 | 8 (80%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
Harderian Gland | (10) | (0) | (0) | (0) | (10) | (10)
Infiltration cellular, lymphocyte | 2 (20%) | – | – | – | 0 | 1 (10%)
Urinary System
Kidney | (10) | (0) | (0) | (0) | (10) | (10)
Casts protein | 0 | – | – | – | 5 (50%) | 0
Infarct | | | | | | 1 (10%)
Mineralization | 10 (100%) | – | – | – | 10 (100%) | 9 (90%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-4 Statistical Analysis of Nonneoplastic Lesions in Female Rats in the Three-month Feed Study of Usnea Lichens

| | 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Liver
Hepatocellular Degeneration
Overall rate^a^ | 0/10 (0.0%) | | –^b^ | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate^c^ | 0/10 (0.0%) | | – | – | – | 0/10 (0.0%) | 1/1 (100.0%)
First incidence (days)^d^ | – | | – | – | – | – | 23
CAFÉ p value^e^ | p ≤ 0.001 | | – | – | – | – | p ≤ 0.001
Average severity^f^ | – | | – | – | – | – | 3.2
Heart
Cardiomyopathy
Overall rate | 3/10 (30.0%) | | – | – | – | 1/10 (10.0%) | 1/10 (10.0%)
Terminal rate | 3/10 (30.0%) | | – | – | – | 1/10 (10.0%) | 1/1 (100.0%)
First incidence (days) | 90 (T) | | – | – | – | 90 (T) | 90 (T)
CAFÉ p value | p = 0.191N | | – | – | – | p = 0.291N | p = 0.291N
Average severity | 1.0 | | – | – | – | 1.0 | 1.0
Adrenal Cortex
Vacuolization Cytoplasmic
Overall rate | | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 8/9 (88.9%)
Terminal rate | | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
First incidence (days) | | – | – | – | – | – | 23
CAFÉ p value | | p ≤ 0.001 | – | – | – | – | p = 0.001
Average severity | | – | – | – | – | – | 3.6
Pituitary Gland
Pars Distalis Cyst
Overall rate | | 0/10 (0.0%) | – | – | – | 2/10 (20.0%) | 0/9 (0.0%)
Terminal rate | | 0/10 (0.0%) | – | – | – | 2/10 (20.0%) | 0/1 (0.0%)
First incidence (days) | | – | – | – | – | 90 (T) | –
CAFÉ p value | | p = 0.643 | – | – | – | p = 0.237 | –
Average severity | | – | – | – | – | 2.0 | –
Thyroid Gland
Ectopic Thymus
Overall rate | | 1/10 (10.0%) | – | – | – | 2/10 (20.0%) | 1/9 (11.1%)
Terminal rate | | 1/10 (10.0%) | – | – | – | 2/10 (20.0%) | 0/1 (0.0%)
First incidence (days) | | 90 (T) | – | – | – | 90 (T) | 23
CAFÉ p value | | p = 0.589 | – | – | – | p = 0.500 | p = 0.430
Average severity | | 5.0 | – | – | – | 5.0 | 5.0
Clitoral Gland
Chronic Active Inflammation
Overall rate | | 2/10 (20.0%) | – | – | – | 0/10 (0.0%) | 0/10 (0.0%)
Terminal rate | | 2/10 (20.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
First incidence (days) | | 90 (T) | – | – | – | – | –
CAFÉ p value | | p = 0.103N | – | – | – | p = 0.237N | p = 0.237N
Average severity | | 2.5 | – | – | – | – | –
Suppurative Inflammation
Overall rate | | 4/10 (40.0%) | – | – | – | 1/10 (10.0%) | 4/10 (40.0%)
Terminal rate | | 4/10 (40.0%) | – | – | – | 1/10 (10.0%) | 1/1 (100.0%)
First incidence (days) | | 90 (T) | – | – | – | 90 (T) | 30
CAFÉ p value | | p = 0.594 | – | – | – | p = 0.152N | p = 0.675
Average severity | | 2.0 | – | – | – | 2.0 | 2.8
Infiltration Cellular
Overall rate | | 1/10 (10.0%) | – | – | – | 0/10 (0.0%) | 2/10 (20.0%)
Terminal rate | | 1/10 (10.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
First incidence (days) | | 90 (T) | – | – | – | – | 27
CAFÉ p value | | p = 0.362N | – | – | – | p = 0.500N | p = 0.500N
Average severity | | 1.0 | – | – | – | – | 1.5
Uterus
Lumen Dilatation
Overall rate | | 2/10 (20.0%) | – | – | – | 3/10 (30.0%) | 1/9 (11.1%)
Terminal rate | | 2/10 (20.0%) | – | – | – | 3/10 (30.0%) | 1/1 (100.0%)
First incidence (days) | | 90 (T) | – | – | – | 90 (T) | 90 (T)
CAFÉ p value | | p = 0.437N | – | – | – | p = 0.500 | p = 0.542N
Average severity | | 3.0 | – | – | – | 3.0 | 2.0
Bone Marrow
Hypocellularity
Overall rate | | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 8/9 (88.9%)
Terminal rate | | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
First incidence (days) | | – | – | – | – | – | 23
CAFÉ p value | | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | | – | – | – | – | – | 3.9
Mesenteric Lymph Node
Hyperplasia
Overall rate | | 4/10 (40.0%) | – | – | – | 4/10 (40.0%) | 0/9 (0.0%)
Terminal rate | | 4/10 (40.0%) | – | – | – | 4/10 (40.0%) | 0/1 (0.0%)
First incidence (days) | | 90 (T) | – | – | – | 90 (T) | –
CAFÉ p value | | p = 0.050N | – | – | – | p = 0.675 | p = 0.054N
Average severity | | 2.0 | – | – | – | 1.8 | –
Mandibular Lymph Node
Hyperplasia
Overall rate | | 2/10 (20.0%) | – | – | – | 0/10 (0.0%) | 0/9 (0.0%)
Terminal rate | | 2/10 (20.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
First incidence (days) | | 90 (T) | – | – | – | – | –
CAFÉ p value | | p = 0.111N | – | – | – | p = 0.237N | p = 0.263N
Average severity | | 2.0 | – | – | – | – | –
Thymus
Atrophy
Overall rate | | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 8/10 (80.0%)
Terminal rate | | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
First incidence (days) | | – | – | – | – | – | 23
CAFÉ p value | | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | | – | – | – | – | – | 3.9
Harderian Gland
Infiltration Cellular
Overall rate | | 2/10 (20.0%) | – | – | – | 0/10 (0.0%) | 1/10 (10.0%)
Terminal rate | | 2/10 (20.0%) | – | – | – | 0/10 (0.0%) | 0/1 (0.0%)
First incidence (days) | | 90 (T) | – | – | – | – | 27
CAFÉ p value | | p = 0.362N | – | – | – | p = 0.237N | p = 0.500N
Average severity | | 1.0 | – | – | – | – | 1.0
Kidney
Mineralization
Overall rate | | 10/10 (100.0%) | – | – | – | 10/10 (100.0%) | 9/10 (90.0%)
Terminal rate | | 10/10 (100.0%) | – | – | – | 10/10 (100.0%) | 1/1 (100.0%)
First incidence (days) | | 90 (T) | – | – | – | 90 (T) | 23
CAFÉ p value | | p = 0.333N | – | – | – | – | p = 0.500N
Average severity | | 4.0 | – | – | – | 3.9 | 3.1
Casts Protein
Overall rate | | 0/10 (0.0%) | – | – | – | 5/10 (50.0%) | 0/10 (0.0%)
Terminal rate | | 0/10 (0.0%) | – | – | – | 5/10 (50.0%) | 0/1 (0.0%)
First incidence (days) | | – | – | – | – | 90 (T) | –
CAFÉ p value | | p = 0.614 | – | – | – | p = 0.016 | –
Average severity | | – | – | – | – | 1.6 | –

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Indicates no data were collected.

^c^ Observed incidence at terminal sacrifice.

^d^ Time to first lesion in days. T indicates terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

Table A-5 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths | 0 | 0 | 0 | 0 | 0 | 0
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (0) | (0) | (0) | (10) | (10)
Inflammation, chronic | 0 | –^b^ | – | – | 0 | 1 (10%)
Tension lipidosis | 2 (20%) | – | – | – | 1 (10%) | 0
Hepatocellular degeneration | 0 | – | – | – | 0 | 10 (100%)
Cardiovascular System
None
Endocrine System
Adrenal Cortex | (10) | (0) | (0) | (0) | (0) | (10)
Accessory adrenal cortical nodule | 0 | – | – | – | – | 1 (10%)
Subcapsular, hyperplasia | 1 (10%) | – | – | – | – | 1 (10%)
Pituitary Gland | (10) | (0) | (0) | (0) | (0) | (10)
Pars distalis, cyst | 1 (10%) | – | – | – | – | 0
Thyroid Gland | (10) | (0) | (0) | (0) | (0) | (10)
Ectopic thymus | 0 | – | – | – | – | 1 (10%)
General Body System
None
Genital System
Preputial Gland | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 2 (20%) | – | – | – | – | 1 (10%)
Inflammation, suppurative | 1 (10%) | – | – | – | – | 0
Hematopoietic System
Lymph Node, Mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Hyperplasia, lymphoid | 1 (10%) | – | – | – | – | 0
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic cell proliferation | 0 | – | – | – | – | 3 (30%)
Hyperplasia, lymphoid | 5 (50%) | – | – | – | – | 4 (40%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-6 Statistical Analysis of Nonneoplastic Lesions in Male Mice in the Three-month Feed Study of Usnea Lichens

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Liver
Hepatocellular Degeneration
Overall rate^a^ | 0/10 (0.0%) | –^b^ | – | – | 0/10 (0.0%) | 10/10 (100.0%)
Terminal rate^c^ | 0/10 (0.0%) | – | – | – | 0/10 (0.0%) | 10/10 (100.0%)
First incidence (days)^d^ | – | – | – | – | – | 90 (T)
CAFÉ p value^e^ | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity^f^ | – | – | – | – | – | 1.8
Tension Lipidosis
Overall rate | 2/10 (20.0%) | – | – | – | 1/10 (10.0%) | 0/10 (0.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | 1/10 (10.0%) | 0/10 (0.0%)
First incidence (days) | 90 (T) | – | – | – | 90 (T) | –
CAFÉ p value | p = 0.140N | – | – | – | p = 0.500N | p = 0.237N
Average severity | 1.0 | – | – | – | 1.0 | –
Preputial Gland
Cyst
Overall rate | 2/10 (20.0%) | – | – | – | – | 1/10 (10.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | – | 1/10 (10.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500N | – | – | – | – | p = 0.500N
Average severity | 2.0 | – | – | – | – | 3.0
Spleen
Hematopoietic Cell Proliferation
Overall rate | 0/10 (0.0%) | – | – | – | – | 3/10 (30.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | – | 3/10 (30.0%)
First incidence (days) | – | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.105 | – | – | – | – | p = 0.105
Average severity | – | – | – | – | – | 2.3
Hyperplasia
Overall rate | 5/10 (50.0%) | – | – | – | – | 4/10 (40.0%)
Terminal rate | 5/10 (50.0%) | – | – | – | – | 4/10 (40.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500N | – | – | – | – | p = 0.500N
Average severity | 2.0 | – | – | – | – | 2.0

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Indicates no data were collected.

^c^ Observed incidence at terminal sacrifice.

^d^ Time to first lesion in days. T indicates terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

Table A-7 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Feed Study of Usnea Lichens^a^

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths
Moribund sacrifice | 1 | 0 | 0 | 0 | 0 | 0
Natural death | 0 | 0 | 0 | 0 | 0 | 1
Survivors
Terminal sacrifice | 9 | 10 | 10 | 10 | 10 | 9
Alimentary System
Intestine Small, Duodenum | (10) | (0) | (0) | (0) | (0) | (9)
Epithelium, hyperplasia | 1 (10%) | –^b^ | – | – | – | 0
Liver | (10) | (0) | (0) | (10) | (10) | (9)
Inflammation, chronic active | 0 | – | – | 2 (20%) | 3 (30%) | 0
Tension lipidosis | 1 (10%) | – | – | 0 | 0 | 0
Vacuolization cytoplasmic | 1 (10%) | – | – | 0 | 0 | 0
Hepatocellular degeneration | 1 (10%) | – | – | 0 | 1 (10%) | 8 (89%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 0 | – | – | – | – | 1 (10%)
Cardiovascular System
None
Endocrine System
Adrenal Cortex | (10) | (0) | (0) | (0) | (0) | (10)
Vacuolization cytoplasmic | 1 (10%) | – | – | – | – | 0
Subcapsular, hyperplasia | 8 (80%) | – | – | – | – | 9 (90%)
Pituitary Gland | (10) | (0) | (0) | (0) | (0) | (10)
Pars distalis, hyperplasia | 1 (10%) | – | – | – | – | 0
Thyroid Gland | (10) | (0) | (0) | (0) | (0) | (10)
Ectopic thymus | 1 (10%) | – | – | – | – | 1 (10%)
General Body System
None
Genital System
Ovary | (10) | (0) | (0) | (10) | (10) | (10)
Atrophy | 1 (10%) | – | – | 0 | 7 (70%) | 10 (100%)
Hematopoietic System
Lymph Node, Mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Hyperplasia, lymphoid | 1 (10%) | – | – | – | – | 3 (30%)
Lymph Node, Mesenteric | (10) | (0) | (0) | (0) | (0) | (9)
Hyperplasia, lymphoid | 2 (20%) | – | – | – | – | 0
Spleen | (10) | (0) | (0) | (0) | (0) | (9)
Depletion lymphoid | 1 (10%) | – | – | – | – | 0
Hematopoietic cell proliferation | 6 (60%) | – | – | – | – | 7 (78%)
Hyperplasia, lymphoid | 3 (30%) | – | – | – | – | 4 (44%)
Pigmentation | 0 | – | – | – | – | 1 (11%)
Thymus | (10) | (0) | (0) | (0) | (0) | (9)
Atrophy | 1 (10%) | – | – | – | – | 0
Integumentary System
None
Musculoskeletal System
Bone, Femur | (10) | (0) | (0) | (0) | (0) | (9)
Hyperplasia | 1 (10%) | – | – | – | – | 0
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Nephropathy | 1 (10%) | – | – | – | – | 0
Glomerulus, amyloid deposition | 1 (10%) | – | – | – | – | 0

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-8 Statistical Analysis of Nonneoplastic Lesions in Female Mice in the Three-month Feed Study of Usnea Lichens

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Liver
Hepatocellular Degeneration
Overall rate^a^ | 1/10 (10.0%) | –^b^ | – | 0/10 (0.0%) | 1/10 (10.0%) | 8/9 (88.9%)
Terminal rate^c^ | 1/9 (11.1%) | – | – | 0/10 (0.0%) | 1/10 (10.0%) | 8/9 (88.9%)
First incidence (days)^d^ | 90 (T) | – | – | – | 90 (T) | 90 (T)
CAFÉ p value^e^ | p ≤ 0.001 | – | – | p = 0.500N | p = 0.763 | p ≤ 0.001
Average severity^f^ | 2.0 | – | – | – | 1.0 | 1.6
Inflammation
Overall rate | 0/10 (0.0%) | – | – | 2/10 (20.0%) | 3/10 (30.0%) | 0/9 (0.0%)
Terminal rate | 0/9 (0.0%) | – | – | 2/10 (20.0%) | 3/10 (30.0%) | 0/9 (0.0%)
First incidence (days) | – | – | – | 90 (T) | 90 (T) | –
CAFÉ p value | p = 0.475N | – | – | p = 0.237 | p = 0.105 | –
Average severity | – | – | – | 1.0 | 1.0 | –
Adrenal Cortex
Subcapsular Hyperplasia
Overall rate | 8/10 (80.0%) | – | – | – | – | 9/10 (90.0%)
Terminal rate | 8/9 (88.9%) | – | – | – | – | 9/9 (100.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500 | – | – | – | – | p = 0.500
Average severity | 1.0 | – | – | – | – | 1.0
Ovary
Atrophy
Overall rate | 1/10 (10.0%) | – | – | 0/10 (0.0%) | 7/10 (70.0%) | 10/10 (100.0%)
Terminal rate | 0/9 (0.0%) | – | – | 0/10 (0.0%) | 7/10 (70.0%) | 9/9 (100.0%)
First incidence (days) | 52 | – | – | – | 90 (T) | 15
CAFÉ p value | p ≤ 0.001 | – | – | p = 0.500N | p = 0.010 | p ≤ 0.001
Average severity | 2.0 | – | – | – | 1.9 | 2.5
Spleen
Hematopoietic Cell Proliferation
Overall rate | 6/10 (60.0%) | – | – | – | – | 7/9 (77.8%)
Terminal rate | 5/9 (55.6%) | – | – | – | – | 7/9 (77.8%)
First incidence (days) | 52 | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.370 | – | – | – | – | p = 0.370
Average severity | 2.0 | – | – | – | – | 2.0
Hyperplasia
Overall rate | 3/10 (30.0%) | – | – | – | – | 4/9 (44.4%)
Terminal rate | 3/9 (33.3%) | – | – | – | – | 4/9 (44.4%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.430 | – | – | – | – | p = 0.430
Average severity | 2.0 | – | – | – | – | 2.5
Mesenteric Lymph Node
Hyperplasia
Overall rate | 2/10 (20.0%) | – | – | – | – | 0/9 (0.0%)
Terminal rate | 2/9 (22.2%) | – | – | – | – | 0/9 (0.0%)
First incidence (days) | 90 (T) | – | – | – | – | –
CAFÉ p value | p = 0.263N | – | – | – | – | p = 0.263N
Average severity | 2.0 | – | – | – | – | –
Mandibular Lymph Node
Hyperplasia
Overall rate | 1/10 (10.0%) | – | – | – | – | 3/10 (30.0%)
Terminal rate | 1/9 (11.1%) | – | – | – | – | 2/9 (22.2%)
First incidence (days) | 90 (T) | – | – | – | – | 15
CAFÉ p value | p = 0.291 | – | – | – | – | p = 0.291
Average severity | 1.0 | – | – | – | – | 1.3

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Indicates no data were collected.

^c^ Observed incidence at terminal sacrifice.

^d^ Time to first lesion in days. T indicates terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.