# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-104

Report Series: NTP Toxicity Report Series

Report Series Number: 104

Official citation: National Toxicology Program (NTP). 2022. NTP technical report on the toxicity studies of (+)-usnic acid (CASRN 7562-61-0) administered in feed to F344/N Nctr rats and B6C3F1/Nctr mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 104.