# References

1 Huneck S, Yoshimura I. Identification of lichen substances. Berlin: Springer-verlag; 1996. 10.1007/978-3-642-85243-5
2 Bjerke JW, Elvebakk A, Domínguez E, Dahlback A. Seasonal trends in usnic acid concentrations of Arctic, alpine and Patagonian populations of the lichen Flavocetraria nivalis. Phytochemistry. 2005; 66(3):337–344. 10.1016/j.phytochem.2004.12.007 15680990
3 Cocchietto M, Skert N, Nimis PL, Sava G. A review on usnic acid, an interesting natural compound. Naturwissenschaften. 2002; 89(4):137–146. 10.1007/s00114-002-0305-3 12061397
4 Ingólfsdóttir K. Usnic acid. Phytochemistry. 2002; 61(7):729–736. 10.1016/S0031-9422(02)00383-7 12453567
5 Ristić S, Ranković B, Kosanić M, Stanojković T, Stamenković S, Vasiljević P, Manojlović I, Manojlović N. Phytochemical study and antioxidant, antimicrobial and anticancer activities of Melanelia subaurifera and Melanelia fuliginosa lichens. J Food Sci Technol. 2016; 53(6):2804–2816. 10.1007/s13197-016-2255-3 27478237
6 Roach JA, Musser SM, Morehouse K, Woo JY. Determination of usnic acid in lichen toxic to elk by liquid chromatography with ultraviolet and tandem mass spectrometry detection. J Agric Food Chem. 2006; 54(7):2484–2490. 10.1021/jf052767m 16569032
7 Shrestha G, El-Naggar AM, St Clair LL, O’Neill KL. Anticancer activities of selected species of North American lichen extracts. Phytother Res. 2015; 29(1):100–107. 10.1002/ptr.5233 25257119
8 Sokolov DN, Luzina OA, Salakhutdinov NF. Usnic acid: Preparation, structure, properties and chemical transformations. Russ Chem Rev. 2012; 81(8):747–768. 10.1070/RC2012v081n08ABEH004245
9 Huneck S, Akinniyi JA, Cameron AF, Connolly JD, Mulholland AG. The absolute configurations of (+)-usnic and (+)-isousnic acid. X-ray analyses of the (−)-α-phenylethylamine derivative of (+)-usnic acid and of (−)-pseudoplacodiolic acid, a new dibenzofuran, from the lichen Rhizoplaca chrysoleuca. Tetrahedron Lett. 1981; 22(4):351–352. 10.1016/0040-4039(81)80095-0
10 Hauck M, Jürgens SR, Willenbruch K, Huneck S, Leuschner C. Dissociation and metal-binding characteristics of yellow lichen substances suggest a relationship with site preferences of lichens. Ann Bot. 2009; 103(1):13–22. 10.1093/aob/mcn202 18977765
11 Merck Index. Monograph number 09893: Usnic acid. In: O’Neil MJ, Heckelman PE, Koch CB, Roman KJ, editors. The Merck Index - An Encyclopedia of Chemicals, Drugs and Biologicals. 14th ed. Whitehouse Station, NJ: Merck Research Laboratories; 2006.
12 Jin JQ, Rao Y, Bian XL, Zeng AG, Yang GD. Solubility of (+)-usnic acid in water, ethanol, acetone, ethyl acetate and n-hexane. J Solution Chem. 2013; 42(5):1018–1027. 10.1007/s10953-013-0010-1
13 Barton DHR, Deflorin AM, Edwards OE. The synthesis of usnic acid. J Chem Soc. 1956;530-534.
14 Taguchi H, Sankawa U, Shibata S. Biosynthesis of natural products. VI. Biosynthesis of usnic acid in lichens. A general scheme of biosynthesis of usnic acid. Chem Pharm Bull (Tokyo). 1969; 17(10):2054–2060. 10.1248/cpb.17.2054 5353559
15 Boehm F, Clarke K, Edge R, Fernandez E, Navaratnam S, Quilhot W, Rancan F, Truscott TG. Lichens—photophysical studies of potential new sunscreens. J Photochem Photobiol B. 2009; 95(1):40–45. 10.1016/j.jphotobiol.2008.12.008 19179091
16 Sharma RK, Jannke PJ. Acidity of usnic acid. Indian J Chem. 1966;4:16–18.
17 Huneck S. The significance of lichens and their metabolites. Naturwissenschaften. 1999; 86(12):559–570. 10.1007/s001140050676 10643590
18 Frankos VH. NTP nomination for usnic acid and usnea barbata herb. College Park, MD: Food and Drug Administration, Division of Dietary Supplement Programs; 2005. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/usnicacid_508.pdf.
19 Hawranik DJ, Anderson KS, Simmonds R, Sorensen JL. The chemoenzymatic synthesis of usnic acid. Bioorg Med Chem Lett. 2009; 19(9):2383–2385. 10.1016/j.bmcl.2009.03.087 19349177
20 Kinoshita Y, Yamamoto Y, Yoshimura I, Kurokawa T, Huneck S. Distribution of optical isomers of usnic and isousnic acids analyzed by high performance liquid chromatography. J Hattori Bot Lab. 1997(83):173–178.
21 Smeds AI. KytÖViita M-M. Determination of usnic and perlatolic acids and identification of olivetoric acids in Northern reindeer lichen (Cladonia stellaris) extracts. Lichenologist. 2010; 42(6):739–749. 10.1017/S002428291000037X
22 Araújo AA, de Melo MG, Rabelo TK, Nunes PS, Santos SL, Serafini MR, Santos MR, Quintans-Júnior LJ, Gelain DP. Review of the biological properties and toxicity of usnic acid. Nat Prod Res. 2015; 29(23):2167–2180. 10.1080/14786419.2015.1007455 25707417
23 Grasso L, Ghirardi PE, Ghione M. Usnic Acid, a selective antimicrobial agent against Streptococcus mutans: A pilot clinical study. Curr Ther Res Clin Exp. 1989;45:1067–1070.
24 Rafanelli S, Bacchilega R, Stanganelli I, Rafanelli A. Contact dermatitis from usnic acid in vaginal ovules. Contact Dermat. 1995; 33(4):271–272. 10.1111/j.1600-0536.1995.tb00484.x 8654084
25 Guo L, Shi Q, Fang JL, Mei N, Ali AA, Lewis SM, Leakey JE, Frankos VH. Review of usnic acid and Usnea barbata toxicity. J Environ Sci Health Part C Environ Carcinog Ecotoxicol Rev. 2008; 26(4):317–338. 10.1080/10590500802533392 19034791
26 Salta M, Wharton JA, Dennington SP, Stoodley P, Stokes KR. Anti-biofilm performance of three natural products against initial bacterial attachment. Int J Mol Sci. 2013; 14(11):21757–21780. 10.3390/ijms141121757 24192819
27 Ghione M, Parrello D, Grasso L. Usnic acid revisited, its activity on oral flora. Chemioterapia. 1988; 7(5):302–305. 2975969
28 Tozatti MG, Ferreira DS, Flauzino LG, Moraes TDS, Martins CH, Groppo M, Andrade e Silva ML, Januário AH, Pauletti PM, Cunhaa WR. Activity of the lichen Usnea steineri and its major metabolites against gram-positive, multidrug-resistant bacteria. Nat Prod Commun. 2016; 11(4):493–496. 10.1177/1934578X1601100419 27396202
29 Safak B, Ciftci IH, Ozdemir M, Kiyildi N, Cetinkaya Z, Aktepe OC, Altindis M. In vitro anti-Helicobacter pylori activity of usnic acid. Phytother Res. 2009; 23(7):955–957. 10.1002/ptr.2690 19367654
30 Ingólfsdóttir K, Chung GA, Skúlason VG, Gissurarson SR, Vilhelmsdóttir M. Antimycobacterial activity of lichen metabolites in vitro. Eur J Pharm Sci. 1998; 6(2):141–144. 10.1016/S0928-0987(97)00078-X 9795033
31 Ferraz-Carvalho RS, Pereira MA, Linhares LA, Lira-Nogueira MC, Cavalcanti IM, Santos-Magalhães NS, Montenegro LM. Effects of the encapsulation of usnic acid into liposomes and interactions with antituberculous agents against multidrug-resistant tuberculosis clinical isolates. Mem Inst Oswaldo Cruz. 2016; 111(5):330–334. 10.1590/0074-02760150454 27143488
32 Nadvorny D, da Silva JB, Lins RD. Anionic form of usnic acid promotes lamellar to nonlamellar transition in DPPC and DOPC membranes. J Phys Chem B. 2014; 118(14):3881–3886. 10.1021/jp412176f 24655129
33 Francolini I, Taresco V, Crisante F, Martinelli A, D’Ilario L, Piozzi A. Water soluble usnic acid-polyacrylamide complexes with enhanced antimicrobial activity against Staphylococcus epidermidis. Int J Mol Sci. 2013; 14(4):7356–7369. 10.3390/ijms14047356 23549269
34 Grumezescu AM, Saviuc C, Chifiriuc MC, Hristu R, Mihaiescu DE, Balaure P, Stanciu G, Lazar V. Inhibitory activity of Fe(3) O(4)/oleic acid/usnic acid-core/shell/extra-shell nanofluid on S. aureus biofilm development. IEEE Trans Nanobioscience. 2011; 10(4):269–274. 10.1109/TNB.2011.2178263 22157076
35 Lira MC, Siqueira-Moura MP, Rolim-Santos HM, Galetti FC, Simioni AR, Santos NP, Tabosa Do Egito ES, Silva CL, Tedesco AC, Santos-Magalhães NS. In vitro uptake and antimycobacterial activity of liposomal usnic acid formulation. J Liposome Res. 2009; 19(1):49–58. 10.1080/08982100802564628 19515007
36 Martinelli A, Bakry A, D’Ilario L, Francolini I, Piozzi A, Taresco V. Release behavior and antibiofilm activity of usnic acid-loaded carboxylated poly(L-lactide) microparticles. Eur J Pharm Biopharm. 2014; 88(2):415–423. 10.1016/j.ejpb.2014.06.002 24929210
37 Ion A, Andronescu E, Rădulescu D, Rădulescu M, Iordache F, Vasile B, Surdu AV, Albu MG, Maniu H, Chifiriuc MC, et al. Biocompatible 3D matrix with antimicrobial properties. Molecules. 2016; 21(1):E115. 10.3390/molecules21010115 26805790
38 Kim S, Greenleaf R, Miller MC, Satish L, Kathju S, Ehrlich G, Post JC, Sotereanos NG, Stoodley P. Mechanical effects, antimicrobial efficacy and cytotoxicity of usnic acid as a biofilm prophylaxis in PMMA. J Mater Sci Mater Med. 2011; 22(12):2773–2780. 10.1007/s10856-011-4445-x 21938390
39 Nithyanand P, Beema Shafreen RM, Muthamil S, Karutha Pandian S. Usnic acid inhibits biofilm formation and virulent morphological traits of Candida albicans. Microbiol Res. 2015;179:20–28. 10.1016/j.micres.2015.06.009 26411891
40 Tay T, Türk AO, Yilmaz M, Türk H, Kivanç M. Evaluation of the antimicrobial activity of the acetone extract of the lichen Ramalina farinacea and its (+)-usnic acid, norstictic acid, and protocetraric acid constituents. Z Naturforsch C J Biosci. 2004; 59(5-6):384–388. 10.1515/znc-2004-5-617 18998406
41 Pires RH, Lucarini R, Mendes-Giannini MJ. Effect of usnic acid on Candida orthopsilosis and C. parapsilosis. Antimicrob Agents Chemother. 2012; 56(1):595–597. 10.1128/AAC.05348-11 22006006
42 Wu J, Zhang M, Ding D, Tan T, Yan B. [Effect of Cladonia alpestris on Trichomonas vaginalis in vitro]. Zhongguo Ji Sheng Chong Xue Yu Ji Sheng Chong Bing Za Zhi. 1995; 13(2):126–129. 7554162
43 Fournet A, Ferreira ME, Rojas de Arias A, Torres de Ortiz S, Inchausti A, Yalaff G, Quilhot W, Fernandez E, Hidalgo ME. Activity of compounds isolated from Chilean lichens against experimental cutaneous leishmaniasis. Comp Biochem Physiol C Pharmacol Toxicol Endocrinol. 1997; 116(1):51–54. 10.1016/S0742-8413(96)00127-2 9080673
44 Si K, Wei L, Yu X, Wu F, Li X, Li C, Cheng Y. Effects of (+)-usnic acid and (+)-usnic acid-liposome on Toxoplasma gondii. Exp Parasitol. 2016;166:68–74. 10.1016/j.exppara.2016.03.021 27004468
45 Lauinger IL, Vivas L, Perozzo R, Stairiker C, Tarun A, Zloh M, Zhang X, Xu H, Tonge PJ, Franzblau SG, et al. Potential of lichen secondary metabolites against Plasmodium liver stage parasites with FAS-II as the potential target. J Nat Prod. 2013; 76(6):1064–1070. 10.1021/np400083k 23806111
46 Yamamoto Y, Miura Y, Kinoshita Y, Higuchi M, Yamada Y, Murakami A, Ohigashi H, Koshimizu K. Screening of tissue cultures and thalli of lichens and some of their active constituents for inhibition of tumor promoter-induced Epstein-Barr virus activation. Chem Pharm Bull (Tokyo). 1995; 43(8):1388–1390. 10.1248/cpb.43.1388 7553984
47 Scirpa P, Scambia G, Masciullo V, Battaglia F, Foti E, Lopez R, Villa P, Malecore M, Mancuso S. [A zinc sulfate and usnic acid preparation used as post-surgical adjuvant therapy in genital lesions by Human Papillomavirus]. Minerva Ginecol. 1999; 51(6):255–260. 10479878
48 Cetin H, Tufan-Cetin O, Turk AO, Tay T, Candan M, Yanikoglu A, Sumbul H. Insecticidal activity of major lichen compounds, (-)- and (+)-usnic acid, against the larvae of house mosquito, Culex pipiens L. Parasitol Res. 2008; 102(6):1277–1279. 10.1007/s00436-008-0905-8 18273644
49 Cetin H, Tufan-Cetin O, Turk AO, Tay T, Candan M, Yanikoglu A, Sumbul H. Larvicidal activity of some secondary lichen metabolites against the mosquito Culiseta longiareolata Macquart (Diptera: Culicidae). Nat Prod Res. 2012; 26(4):350–355. 10.1080/14786411003774296 21452097
50 Takai M, Uehara Y, Beisler JA. Usnic acid derivatives as potential antineoplastic agents. J Med Chem. 1979; 22(11):1380–1384. 10.1021/jm00197a019 160461
51 Cardarelli M, Serino G, Campanella L, Ercole P, De Cicco Nardone F, Alesiani O, Rossiello F. Antimitotic effects of usnic acid on different biological systems. Cell Mol Life Sci. 1997; 53(8):667–672. 10.1007/s000180050086 9351470
52 Kristmundsdóttir T, Aradóttir HA, Ingólfsdóttir K, Ogmundsdóttir HM. Solubilization of the lichen metabolite (+)-usnic acid for testing in tissue culture. J Pharm Pharmacol. 2002; 54(11):1447–1452. 10.1211/002235702225 12495546
53 Kumar KC, Müller K. Lichen metabolites. 2. Antiproliferative and cytotoxic activity of gyrophoric, usnic, and diffractaic acid on human keratinocyte growth. J Nat Prod. 1999; 62(6):821–823. 10.1021/np980378z 10395495
54 Kapoor S. Usnic acid and its evolving role as a potent antineoplastic agent. Toxicol Pathol. 2016; 44(6):918. 10.1177/0192623316648800 27465778
55 Bačkorová M, Bačkor M, Mikeš J, Jendželovský R, Fedoročko P. Variable responses of different human cancer cells to the lichen compounds parietin, atranorin, usnic acid and gyrophoric acid. Toxicol In Vitro. 2011; 25(1):37–44. 10.1016/j.tiv.2010.09.004 20837130
56 Bačkorová M, Jendželovský R, Kello M, Bačkor M, Mikeš J, Fedoročko P. Lichen secondary metabolites are responsible for induction of apoptosis in HT-29 and A2780 human cancer cell lines. Toxicol In Vitro. 2012; 26(3):462–468. 10.1016/j.tiv.2012.01.017 22285236
57 Sahu SC, Amankwa-Sakyi M, O’Donnell MW Jr, Sprando RL. Effects of usnic acid exposure on human hepatoblastoma HepG2 cells in culture. J Appl Toxicol. 2012; 32(9):722–730. 10.1002/jat.1721 21953288
58 Brisdelli F, Perilli M, Sellitri D, Piovano M, Garbarino JA, Nicoletti M, Bozzi A, Amicosante G, Celenza G. Cytotoxic activity and antioxidant capacity of purified lichen metabolites: An in vitro study. Phytother Res. 2013; 27(3):431–437. 10.1002/ptr.4739 22628260
59 Singh N, Nambiar D, Kale RK, Singh RP. Usnic acid inhibits growth and induces cell cycle arrest and apoptosis in human lung carcinoma A549 cells. Nutr Cancer. 2013; 65 Suppl 1:36–43. 10.1080/01635581.2013.785007 23682781
60 Chen S, Dobrovolsky VN, Liu F, Wu Y, Zhang Z, Mei N, Guo L. The role of autophagy in usnic acid-induced toxicity in hepatic cells. Toxicol Sci. 2014; 142(1):33–44. 10.1093/toxsci/kfu154 25078063
61 Bruno M, Trucchi B, Burlando B, Ranzato E, Martinotti S, Akkol EK, Süntar I, Keleş H, Verotta L. (+)-Usnic acid enamines with remarkable cicatrizing properties. Bioorg Med Chem. 2013; 21(7):1834–1843. 10.1016/j.bmc.2013.01.045 23434134
62 Yang Y, Nguyen TT, Jeong MH, Crişan F, Yu YH, Ha HH, Choi KH, Jeong HG, Jeong TC, Lee KY, et al. Inhibitory activity of (+)-usnic acid against non-small cell lung cancer cell motility. PLoS One. 2016; 11(1):e0146575. 10.1371/journal.pone.0146575 26751081
63 Einarsdóttir E, Groeneweg J, Björnsdóttir GG, Harethardottir G, Omarsdóttir S, Ingólfsdóttir K, Ogmundsdóttir HM. Cellular mechanisms of the anticancer effects of the lichen compound usnic acid. Planta Med. 2010; 76(10):969–974. 10.1055/s-0029-1240851 20143294
64 Song Y, Dai F, Zhai D, Dong Y, Zhang J, Lu B, Luo J, Liu M, Yi Z. Usnic acid inhibits breast tumor angiogenesis and growth by suppressing VEGFR2-mediated AKT and ERK1/2 signaling pathways. Angiogenesis. 2012; 15(3):421–432. 10.1007/s10456-012-9270-4 22669534
65 Vijayakumar CS, Viswanathan S, Reddy MK, Parvathavarthini S, Kundu AB, Sukumar E. Anti-inflammatory activity of (+)-usnic acid. Fitoterapia. 2000; 71(5):564–566. 10.1016/S0367-326X(00)00209-4 11449509
66 Su ZQ, Mo ZZ, Liao JB, Feng XX, Liang YZ, Zhang X, Liu YH, Chen XY, Chen ZW, Su ZR, et al. Usnic acid protects LPS-induced acute lung injury in mice through attenuating inflammatory responses and oxidative stress. Int Immunopharmacol. 2014; 22(2):371–378. 10.1016/j.intimp.2014.06.043 25068825
67 Jin JQ, Li CQ, He LC. Down-regulatory effect of usnic acid on nuclear factor-kappaB-dependent tumor necrosis factor-alpha and inducible nitric oxide synthase expression in lipopolysaccharide-stimulated macrophages RAW 264.7. Phytother Res. 2008; 22(12):1605–1609. 10.1002/ptr.2531 19003951
68 Okuyama E, Umeyama K, Yamazaki M, Kinoshita Y, Yamamoto Y. Usnic acid and diffractaic acid as analgesic and antipyretic components of Usnea diffracta. Planta Med. 1995; 61(2):113–115. 10.1055/s-2006-958027 7753915
69 Krishna DR, Venkataramana D. Pharmacokinetics of D(+)-usnic acid in rabbits after intravenous and oral administration. Drug Metab Dispos. 1992; 20(6):909–911. 1362945
70 Krishna DR, Ramana DV, Mamidi NV. In vitro protein binding and tissue distribution of D(+) usnic acid. Drug Metabol Drug Interact. 1995; 12(1):53–64. 10.1515/DMDI.1995.12.1.53 7555002
71 Serafini MR, Detoni CB, Guterres SS, da Silva GF, de Souza Araújo AA. Determination of in vitro usnic acid delivery into porcine skin using a HPLC method. J Chromatogr Sci. 2015; 53(5):757–760. 10.1093/chromsci/bmu120 25260845
72 Foti RS, Dickmann LJ, Davis JA, Greene RJ, Hill JJ, Howard ML, Pearson JT, Rock DA, Tay JC, Wahlstrom JL, et al. Metabolism and related human risk factors for hepatic damage by usnic acid containing nutritional supplements. Xenobiotica. 2008; 38(3):264–280. 10.1080/00498250701802514 18274956
73 Cheng YB, Wei LL, Gu N, Si KW, Shi L, Li XQ, Li C, Yuan YK. [Oral acute toxicity of (+)-usnic acid in mice and its cytotoxicity in rat cardiac fibroblasts]. Nan Fang Yi Ke Da Xue Xue Bao. 2009; 29(8):1749–1751. 19726328
74 Shtro AA, Zarubaev VV, Luzina OA, Sokolov DN, Salakhutdinov NF. Derivatives of usnic acid inhibit broad range of influenza viruses and protect mice from lethal influenza infection. Antivir Chem Chemother. 2015; 24(3-4):92–98. 10.1177/2040206616636992 27022094
75 Marshak A, Kuschner M. The action of streptomycin and usnic acid on the development of tuberculosis in guinea pigs. Public Health Rep. 1950; 65(5):131–144. 10.2307/4587227 15405524
76 da Silva Santos NP, Nascimento SC, Wanderley MS, Pontes-Filho NT, da Silva JF, de Castro CM, Pereira EC, da Silva NH, Honda NK, Santos-Magalhães NS. Nanoencapsulation of usnic acid: An attempt to improve antitumour activity and reduce hepatotoxicity. Eur J Pharm Biopharm. 2006; 64(2):154–160. 10.1016/j.ejpb.2006.05.018 16899355
77 Ribeiro-Costa RM, Alves AJ, Santos NP, Nascimento SC, Gonçalves EC, Silva NH, Honda NK, Santos-Magalhães NS. In vitro and in vivo properties of usnic acid encapsulated into PLGA-microspheres. J Microencapsul. 2004; 21(4):371–384. 10.1080/02652040410001673919 15513745
78 Pramyothin P, Janthasoot W, Pongnimitprasert N, Phrukudom S, Ruangrungsi N. Hepatotoxic effect of (+)usnic acid from Usnea siamensis Wainio in rats, isolated rat hepatocytes and isolated rat liver mitochondria. J Ethnopharmacol. 2004; 90(2-3):381–387. 10.1016/j.jep.2003.10.019 15013205
79 Lu X, Zhao Q, Tian Y, Xiao S, Jin T, Fan X. A metabonomic characterization of (+)-usnic acid-induced liver injury by gas chromatography-mass spectrometry-based metabolic profiling of the plasma and liver in rat. Int J Toxicol. 2011; 30(5):478–491. 10.1177/1091581811414436 21878557
80 Yokouchi Y, Imaoka M, Niino N, Kiyosawa N, Sayama A, Jindo T. (+)-Usnic acid-induced myocardial toxicity in rats. Toxicol Pathol. 2015; 43(3):424–434. 10.1177/0192623313504308 24178575
81 Dailey RN, Montgomery DL, Ingram JT, Siemion R, Vasquez M, Raisbeck MF. Toxicity of the lichen secondary metabolite (+)-usnic acid in domestic sheep. Vet Pathol. 2008; 45(1):19–25. 10.1354/vp.45-1-19 18192570
82 Jiang MD, Zheng SM, Xu H, Zeng WZ, Zhang Y, Sun HP, Wang YX, Qin JP, Wu XL. An experimental study of extracellular signal-regulated kinase and its interventional treatments in hepatic fibrosis. Hepatobiliary Pancreat Dis Int. 2008; 7(1):51–57. 18234639
83 Cook WE, Raisbeck MF, Cornish TE, Williams ES, Brown B, Hiatt G, Kreeger TJ. Paresis and death in elk (Cervus elaphus) due to lichen intoxication in Wyoming. J Wildl Dis. 2007; 43(3):498–503. 10.7589/0090-3558-43.3.498 17699088
84 Romagni JG, Meazza G, Nanayakkara NP, Dayan FE. The phytotoxic lichen metabolite, usnic acid, is a potent inhibitor of plant p-hydroxyphenylpyruvate dioxygenase. FEBS Lett. 2000; 480(2-3):301–305. 10.1016/S0014-5793(00)01907-4 11034349
85 Bačkor M, Klemová K, Backorová M, Ivanova V. Comparison of the phytotoxic effects of usnic acid on cultures of free-living alga Scenedesmus quadricauda and aposymbiotically grown lichen photobiont Trebouxia erici. J Chem Ecol. 2010; 36(4):405–411. 10.1007/s10886-010-9776-4 20306219
86 Backor M, Gaburjáková J, Hudák J, Ziegler W. The biological role of secondary metabolites from lichens. 1. The influence of usnic acid on bimolecular lipid membranes. Acta Facultatis Rerum Naturalium Universitatis Comenianae. 1997;29:67–71.
87 Mitchell P. Vectorial chemistry and the molecular mechanics of chemiosmotic coupling: Power transmission by proticity. Biochem Soc Trans. 1976; 4(3):399–430. 10.1042/bst0040399 137147
88 Abo-Khatwa AN, al-Robai AA, al-Jawhari DA. Lichen acids as uncouplers of oxidative phosphorylation of mouse-liver mitochondria. Nat Toxins. 1996; 4(2):96–102. 10.1002/19960402NT7 8726330
89 Han D, Matsumaru K, Rettori D, Kaplowitz N. Usnic acid-induced necrosis of cultured mouse hepatocytes: Inhibition of mitochondrial function and oxidative stress. Biochem Pharmacol. 2004; 67(3):439–451. 10.1016/j.bcp.2003.09.032 15037196
90 Shibamoto T, Wei CL. Mutagenicity of lichen constituents. Environ Mutagen. 1984; 6(5):757–762. 10.1002/em.2860060512 6236972
91 Johnson RB, Feldott G, Lardy HA. The mode of action of the antibiotic, usnic acid. Arch Biochem. 1950; 28(3):317–323. 14790772
92 Moreira CT, Oliveira AL, Comar JF, Peralta RM, Bracht A. Harmful effects of usnic acid on hepatic metabolism. Chem Biol Interact. 2013; 203(2):502–511. 10.1016/j.cbi.2013.02.001 23422721
93 Bessadottir M, Egilsson M, Einarsdottir E, Magnusdottir IH, Ogmundsdottir MH, Omarsdottir S, Ogmundsdottir HM. Proton-shuttling lichen compound usnic acid affects mitochondrial and lysosomal function in cancer cells. PLoS One. 2012; 7(12):e51296. 10.1371/journal.pone.0051296 23227259
94 Colman E. Dinitrophenol and obesity: An early twentieth-century regulatory dilemma. Regul Toxicol Pharmacol. 2007; 48(2):115–117. 10.1016/j.yrtph.2007.03.006 17475379
95 Hsiao AL, Santucci KA, Seo-Mayer P, Mariappan MR, Hodsdon ME, Banasiak KJ, Baum CR. Pediatric fatality following ingestion of dinitrophenol: Postmortem identification of a “dietary supplement”. Clin Toxicol (Phila). 2005; 43(4):281–285. 16035205
96 Miranda EJ, McIntyre IM, Parker DR, Gary RD, Logan BK. Two deaths attributed to the use of 2,4-dinitrophenol. J Anal Toxicol. 2006; 30(3):219–222. 10.1093/jat/30.3.219 16803658
97 Favreau JT, Ryu ML, Braunstein G, Orshansky G, Park SS, Coody GL, Love LA, Fong TL. Severe hepatotoxicity associated with the dietary supplement LipoKinetix. Ann Intern Med. 2002; 136(8):590–595. 10.7326/0003-4819-136-8-200204160-00008 11955027
98 Neff GW, Reddy KR, Durazo FA, Meyer D, Marrero R, Kaplowitz N. Severe hepatotoxicity associated with the use of weight loss diet supplements containing ma huang or usnic acid. J Hepatol. 2004; 41(6):1062–1064. 10.1016/j.jhep.2004.06.028 15582145
99 Sanchez W, Maple JT, Burgart LJ, Kamath PS. Severe hepatotoxicity associated with use of a dietary supplement containing usnic acid. Mayo Clin Proc. 2006; 81(4):541–544. 10.4065/81.4.541 16610575
100 Durazo FA, Lassman C, Han SH, Saab S, Lee NP, Kawano M, Saggi B, Gordon S, Farmer DG, Yersiz H, et al. Fulminant liver failure due to usnic acid for weight loss. Am J Gastroenterol. 2004; 99(5):950–952. 10.1111/j.1572-0241.2004.04165.x 15128366
101 Anonymous. FDA warns against dietary supplement. OBGYN NET; 2001. https://web.archive.org/web/20041119151559/http://www.obgyn.net/newsrx/general_health-Nutriceuticals-20011217-11.asp [Accessed: May 25, 2011]
102 al-Bekairi AM, Qureshi S, Chaudhry MA, Krishna DR, Shah AH. Mitodepressive, clastogenic and biochemical effects of (+)-usnic acid in mice. J Ethnopharmacol. 1991; 33(3):217–220. 10.1016/0378-8741(91)90079-S 1833591
103 Brown JP. A review of the genetic effects of naturally occurring flavonoids, anthraquinones and related compounds. Mutat Res. 1980; 75(3):243–277. 10.1016/0165-1110(80)90029-9 6770263
104 National Toxicology Program (NTP). Genotoxicity test of usnic acid in Salmonella. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2006. https://manticore.niehs.nih.gov/datasets/search/trf?casrn=125-46-2 [Accessed: December 9, 2018]
105 Koparal AT, Tüylü BA, Türk H. In vitro cytotoxic activities of (+)-usnic acid and (-)-usnic acid on V79, A549, and human lymphocyte cells and their non-genotoxicity on human lymphocytes. Nat Prod Res. 2006; 20(14):1300–1307. 10.1080/14786410601101910 17393655
106 Polat Z, Aydın E, Türkez H, Aslan A. In vitro risk assessment of usnic acid. Toxicol Ind Health. 2016; 32(3):468–475. 10.1177/0748233713504811 24193043
107 Leandro LF, Munari CC, Sato VL, Alves JM, de Oliveira PF, Mastrocola DF, Martins SP, Moraes TdS, de Oliveira AI, Tozatti MG et al. Assessment of the genotoxicity and antigenotoxicity of (+)-usnic acid in V79 cells and Swiss mice by the micronucleus and comet assays. Mutat Res. 2013; 753(2):101–106. 10.1016/j.mrgentox.2013.03.006 23545536
108 Center for Food Safety and Applied Nutrition (CFSAN). Letter to distributor of hazardous dietary supplement, LipoKenetix. Food and Drug Administration, Center for Food Safety and Applied Nutrition; 2001. http://www.cfsan.fda.gov/~dms/ds-ltr26.html [Accessed: July 10, 2012]
109 Center for Food Safety and Applied Nutrition (CFSAN). FDA warns consumers not to use the dietary supplement LipoKenetix. Food and Drug Administration, Center for Food Safety and Applied Nutrition; 2011. http://www.cfsan.fda.gov/~dms/ds-lipo.html [Accessed: July 10, 2012]
110 National Toxicology Program (NTP). NTP technical report on the toxicity studies of usnea lichens containing (+/-)-usnic acid (CASRN 125-46-2) administered in feed to F344/N Nctr rats and B6C3F1/Nctr mice. Research Triangle Park, NC: National Institute of Environmental Health Sciences, National Toxicology Program; 2021. NTP Toxicity Report No. 105 (in progress).
111 National Toxicology Program (NTP). Specifications for the conduct of studies to evaluate the toxic and carcinogenic potential of chemical, biological and physical agents in laboratory animals for the National Toxicology Program (NTP). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2006.
112 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
113 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
114 Cox DR. Regression models and life-tables. J R Stat Soc B. 1972; 34(2):187–202.
115 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
116 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
117 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
118 Armitage P. Tests for linear trends in proportions and frequencies. Biometrics. 1955; 11(3):375–386. 10.2307/3001775
119 Skouteris GG, McMenamin M. Transforming growth factor-alpha-induced DNA synthesis and c-myc expression in primary rat hepatocyte cultures is modulated by indomethacin. Biochem J. 1992; 281(Pt 3):729–733. 10.1042/bj2810729 1531590
120 Fisher RA. On the interpretation of χ2 from contingency tables, and the calculation of P. J R Stat Soc. 1922; 85(1):87–94. 10.2307/2340521
121 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
122 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
123 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
124 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. 10.2307/2531963 3567307
125 Sun J, Slavov S, Schnackenberg LK, Ando Y, Greenhaw J, Yang X, Salminen W, Mendrick DL, Beger R. Identification of a metabolic biomarker panel in rats for prediction of acute and idiosyncratic hepatotoxicity. Comput Struct Biotechnol J. 2014; 10(17):78–89. 10.1016/j.csbj.2014.08.001 25379137
126 Diamondstone TI. Assay of tyrosine transaminase activity by conversion of p-hydroxyphenylpyruvate to p-hydroxybenzaldehyde. Anal Biochem. 1966; 16(3):395–401. 10.1016/0003-2697(66)90220-X
127 Arvaniti K, Deshaies Y, Richard D. Effect of leptin on energy balance does not require the presence of intact adrenals. Am J Physiol. 1998; 275(1):R105–R111. 10.1152/ajpregu.1998.275.1.R105 9688967
128 Echtay KS. Mitochondrial uncoupling proteins—what is their physiological role? Free Radic Biol Med. 2007; 43(10):1351–1371. 10.1016/j.freeradbiomed.2007.08.011 17936181
129 Dertinger SD, Bishop ME, McNamee JP, Hayashi M, Suzuki T, Asano N, Nakajima M, Saito J, Moore M, Torous DK, et al. Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: I. Intra- and interlaboratory comparison with microscopic scoring. Toxicol Sci. 2006; 94(1):83–91. 10.1093/toxsci/kfl075 16888078
130 Dertinger SD, Torous DK, Tometsko KR. Simple and reliable enumeration of micronucleated reticulocytes with a single-laser flow cytometer. Mutat Res. 1996; 371(3-4):283–292. 10.1016/S0165-1218(96)90117-2 9008730
131 Dobrovolsky VN, Shaddock JG, Mittelstaedt RA, Bishop ME, Lewis SM, Lee FW, Aidoo A, Leakey JE, Dunnick JK, Heflich RH. Frequency of Hprt mutant lymphocytes and micronucleated erythrocytes in p53-haplodeficient mice treated perinatally with AZT and AZT in combination with 3TC. Environ Mol Mutagen. 2007; 48(3-4):270–282. 10.1002/em.20280 17358030