# Discussion

The selection of exposure levels of (+)-usnic acid for F344/N Nctr rats and B6C3F1/Nctr mice was based on a 2-week range-finding study conducted prior to the 3-month study (Appendix J) in which feed concentrations of 1,250 and 2,500 ppm in rats and 1,200 ppm in mice caused rapid weight loss and some morbidity. The selected exposure levels corresponded to target doses of 5, 10, 30, 100, and 200 mg/kg body weight/day (mg/kg/day) for both rats and mice, calculated from historical feed consumption and body weight data from the relevant strains. Human exposure to formulations associated with hepatotoxicity was approximately 1–12 mg/kg/day.^18^ The observed daily doses calculated from the study data correlated closely for the rats but were higher than the target dose in mice (Appendix F).

(+)-Usnic acid was relatively nontoxic to female F344/N Nctr rats and male and female B6C3F1/Nctr mice at the doses used in this 3-month feed study. In contrast, exposure of male F344/N Nctr rats to (+)-usnic acid concentrations of 360 and 720 ppm in feed resulted in increased incidence and severity of hepatocellular degeneration and hepatic inflammation. Males from the 720 ppm exposure group also had higher incidence of hydronephrosis. Although serum alanine aminotransferase levels were moderately increased (e.g., by 17–41 U/l, Table C-1) in the highest exposure groups of both male mice and female rats relative to controls, the increases were much less than those generally observed in rats treated with hepatotoxic doses of acetaminophen or carbon tetrachloride (e.g., 390–460 U/l, Sun et al.^125^) or those observed in patients with (+)-usnic acid-associated severe hepatotoxicity (e.g., 1,000–14,000 U/l^97^). These observations suggest that (+)-usnic acid-induced hepatotoxicity in this study did not produce severe necrosis. Exposure to higher concentrations of (+)-usnic acid equivalent to 100 or 200 mg/kg/day for 2-weeks (Appendix J) was significantly more toxic, producing clear hepatocellular degeneration in both male and female (200 mg/kg/day only) mice and in male and female rats. Greater toxicity was observed in rats for the 2-week study, with some mortality occurring in the first week of exposure.

Hepatotoxicity has occurred in humans when (+)-usnic acid is used as a weight-loss supplement and “fat burner.” In this study rats exposed to 720 ppm had significantly lower body weights compared to the control group, but not in mice exposed to 360 ppm. In the 2-week range-finding study significant weight loss was observed at exposure levels of 1,250 and 2,500 ppm in rats and 1,200 ppm in mice.

(+)-Usnic acid is known to be an uncoupler of mitochondrial oxidative phosphorylation^25^ and this uncoupling activity is thought to be the basis of (+)-usnic acid-induced hepatotoxicity due to its resultant depletion of intracellular ATP concentrations.^25,88,89^ Significant ATP depletion was observed in livers of male rats exposed for 2 weeks to (+)-usnic acid at exposure concentrations of 120, 360, 1,250, and 2,500 ppm (Table J-5), whereas liver damage was noted in only the 1,250 and 2,500 ppm exposure groups (Table J-3). While this supports the hypothesis that mitochondrial uncoupling provides a mechanistic basis for (+)-usnic acid-induced hepatotoxicity, it implies that severe prolonged depletion of ATP is required for hepatotoxicity to develop.

When isolated mouse or rat hepatocytes were exposed to (+)-usnic acid concentrations in the range of 1–10 µM, intracellular ATP concentrations are rapidly depleted to <5% of initial values and the cells die.^25,89^ In contrast, when female F344/N Nctr rats or male B6C3F1/Nctr mice were exposed to 360 or 180 ppm (+)-usnic acid, respectively, for 14 days, which did not result in overt hepatotoxicity, hepatic (+)-usnic acid levels increased to steady-state concentrations of 75–80 or 38–58 µM, respectively (Appendix K). In female F344/N Nctr rats fed control feed for 14 days, hepatic ATP concentrations were measured as 1.09 ± 0.13 µmol/g, whereas hepatic ATP levels in rats exposed to 360 ppm (+)-usnic acid were measured as 0.60 ± 0.14 µmol/g (55% of control, p = 0.16, Table J-5). In male B6C3F1/Nctr mice fed control feed for 14 days, hepatic ATP concentrations were measured as 1.64 ± 0.21 µmol/g, whereas hepatic ATP levels in male mice exposed to 180 ppm (+)-usnic acid were measured as 0.85 ± 0.22 µmol/g (52% of control, p = 0.016, Table J-6). This suggests that hepatocytes in vitro are considerably more susceptible to (+)-usnic acid-induced ATP depletion than hepatocytes in vivo and that rats are more susceptible than mice. In both rats and mice, hepatic (+)-usnic acid had accumulated after 14 days exposure in feed to levels that were more than fourfold greater than concentrations that are lethal to cultured hepatocytes, but hepatic ATP concentrations had decreased by <50%. Interestingly, hepatic tyrosine aminotransferase activity was shown to be induced by (+)-usnic acid exposure in the male rats used in the 14-day study (Appendix J). Tyrosine aminotransferase is a rate-limiting enzyme that facilitates catabolism of tyrosine.^126^ Mammalian mitochondria generally express membrane uncoupling proteins, which generate heat at the expense of ATP synthesis.^127,128^ Mice express higher levels of uncoupling protein UCP-1 than rats because they require a greater capacity for heat generation due to their smaller body size. UCP-1 is upregulated by leptin and downregulated by corticosterone in rodents.^127^ It is probable that rodents compensate for the uncoupling action of (+)-usnic acid by downregulating UCP-1 expression. Serum leptin concentrations were found to be depleted to <10% of control values in female F344/N Nctr rats exposed to 1,250 ppm (+)-usnic acid for 14 days (Appendix J), which may be a mechanism through which the animals reduce UCP-1 expression. Because mice express higher UCP-1 concentrations than rats, it is probable that they have a greater capacity to compensate for (+)-usnic acid toxicity.

Exposure of F344/N Nctr rats and B6C3F1/Nctr mice to (+)-usnic acid in feed for 3 months resulted in significant hepatotoxicity in male rats at exposure levels of 360 and 720 ppm. Moderate increases in serum creatinine, blood urea nitrogen (BUN), and alanine aminotransferase activity were observed in female rats at exposure levels of 720 ppm. In male mice, moderate but significant increases in alanine aminotransferase and alkaline phosphatase were observed at exposure levels of 360 ppm, moderate significant increases in BUN were observed at exposure levels of 180 and 360 ppm, whereas moderate significant increases in serum creatinine were observed at exposure levels of 60, 180, and 360 ppm. There were significantly fewer female rats cycling in the 720 ppm group than in the control group, due to extended diestrus. Significant body weight decreases were achieved at exposure levels of 720 ppm in male and female rats. Exposure to 600 ppm (+)-usnic acid for 14 days significantly increased the incidence of micronuclei in erythrocytes or reticulocytes from both male and female B6C3F1/Nctr mice; exposure to 1,200 ppm significantly increased the incidence of micronuclei in reticulocytes in male B6C3F1/Nctr mice. No-observed-adverse-effect levels (NOAELs) of 120 ppm and 30 ppm of (+)-usnic acid administered in feed were established for F344/N Nctr rats and B6C3F1/Nctr mice, respectively, on the basis of the results of these subchronic studies.