# Results

## Rats

### Survival

Disposition data and survival probabilities for the male and female F344/N Nctr rats are shown in Table 3. All rats in all exposure groups survived to terminal sacrifice. No further statistical analysis was performed due to all animals surviving until the end of the study.

Table 3 Survival, Disposition, and Body Weights of Rats in the Three-month Feed Study of (+)-Usnic Acid

Parameter^a^ | 0 ppm | 30 ppm (2.5)^b^ | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 720 ppm (60)
Male
Rats Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 0
Moribund | 0 | 0 | 0 | 0 | 0 | 0
Rats Surviving to Study Termination | 10 | 10 | 10 | 10 | 10 | 10
Probability of Survival to End of Study | 100% | 100% | 100% | 100% | 100% | 100%
Mean Survival (Days)^c^ | 94 | 94 | 94 | 94 | 94 | 94
Initial Body Weight (g)^d^ | 194.4 ± 5.1 | 196.2 ± 3.9 | 195.4 ± 5.1 | 194.5 ± 3.8 | 197.1 ± 5.5 | 195.3 ± 4.3
Final Body Weight (g)^d^ | 359.4 ± 5.5*** | 357.1 ± 5.1 | 342.6 ± 6.1* | 353.0 ± 4.2 | 350.5 ± 6.0 | 334.2 ± 3.5***
Change in Body Weight (g) | 165.0 | 160.9 | 147.2 | 158.5 | 153.4 | 138.9
Final Weight as % of Controls | –^e^ | 99.4 | 95.3 | 98.2 | 97.5 | 93.0
Observed Dose (mg/kg/day)^f^ | – | 2.26 ± 0.08 | 4.45 ± 0.13 | 9.09 ± 0.31 | 27.78 ± 0.80 | 59.93 ± 1.80
Female
Rats Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 0
Moribund | 0 | 0 | 0 | 0 | 0 | 0
Rats Surviving to Study Termination | 10 | 10 | 10 | 10 | 10 | 10
Probability of Survival to End of Study | 100% | 100% | 100% | 100% | 100% | 100%
Mean Survival (Days) | 94 | 94 | 94 | 94 | 94 | 94
Initial Body Weight (g) | 140.4 ± 1.8 | 141.5 ± 1.6 | 144.5 ± 2.0 | 139.3 ± 2.0 | 139.6 ± 2.2 | 141.5 ± 2.4
Final Body Weight (g) | 209.1 ± 4.4*** | 212.6 ± 3.2 | 210.2 ± 3.6 | 205.5 ± 4.0 | 195.8 ± 3.2** | 178.7 ± 2.1***
Change in Body Weight (g) | 68.7 | 71.1 | 65.7 | 66.2 | 56.2 | 37.2
Final Weight % of Controls | – | 101.7 | 100.5 | 98.3 | 93.6 | 85.5
Observed Dose (mg/kg/day) | – | 2.91 ± 0.07 | 5.51 ± 0.14 | 11.64 ± 0.28 | 35.64 ± 0.56 | 76.98 ± 0.96

^a^ Complete details of the dosing schedule are given in the methods section.

^b^ Denotes target dose as mg (+)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Animals were assigned to the study for 94 days but were exposed to dosed feed for 90 days.

^d^ Body weight (g) as mean ± standard error. Asterisks denote significant trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^e^ Not applicable.

^f^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving rats in each exposed group. Observed feed consumption values do not correct for spillage. Data presented as mean ± standard error for the 13 weekly values.

### Body and Organ Weight Analysis

Body weight curves are shown in Figure 4. The effect of (+)-usnic acid exposure on body weight was of interest because human exposure is primarily due to its use as a weight-loss agent. There were statistically significant differences in mean body weights between the high exposed group (720 ppm) and the control group for both females and males. Mean body weights for females and males were consistently lower (4.2%–14.5% and 3.0%–7.9%, respectively) for the 720 ppm group than for the control group throughout the study. Mean body weights for females in the 360 ppm group were lower (6.4% at week 13) than in the control group. Mean body weights for males in the 60 ppm group were lower (4.7% at week 13) than in the control group (see Appendix D for details).

Figure 4

Growth Curves for Male and Female Rats Exposed to (+)-Usnic Acid in Feed for Three Months

Plotted as mean body weights of each exposure group.

Absolute and relative organ weights are reported in Appendix E. Mean absolute and relative liver weights for females and males were higher for the 720 ppm group than for controls. Relative liver weight was higher at 360 ppm for females. Mean weights for male left and right (relative only) testis and left epididymis in the 720 ppm group were higher compared to the control group.

The body weight data and feed consumption data (Appendix D and Appendix F) were used to estimate the actual dose of (+)-usnic acid in each exposure group on days 28, 46, and 88 of the study. The data are shown in Table F-5 and summarized in Table 3. The observed dosage was similar to the target dose of (+)-usnic acid for all exposure groups except the females in the 720 ppm group in which the observed dose was 28% greater than the target dose.

### Pathology and Statistical Analyses

The only gross observation in rats that may have had an exposure relationship was renal pelvis dilatation (hydronephrosis) present in males. The remainder of the gross observations were considered to be common background changes.

While no exposure-related histopathological changes were noted in females, the incidence of renal nephropathy was significantly increased (10/10, average score 1.2 versus 2/10, average score 1.0 for the control group p ≤ 0.001; see Appendix A) in the 720 ppm group relative to the control group. Renal nephropathy is a common lesion in F344/N Nctr rats and was observed in 10/10 of the male controls. Serum alanine aminotransferase (ALT), blood urea nitrogen (BUN), and creatinine concentrations were moderately increased in the 720 ppm groups relative to the control group in female rats, and creatinine was moderately increased in the 720 ppm group in males (Appendix C).

The histopathological changes observed in male rats that were considered exposure-related are summarized in Table 4 and Figure 5, Figure 6, Figure 7, and Figure 8. Hepatocellular degeneration (Figure 8.) was observed in male rats from the 60 and 120 ppm exposure groups and had increased incidence and severity in the 360 and 720 ppm exposure groups relative to the control group. The affected animals displayed one or more of the following changes: cell swelling as well as cell contraction, cytoplasmic vacuolization or clearing, clumping (increased densities) of organelles, and in many animals an increased cytoplasmic eosinophilia. These lesions were primarily noted in the centrilobular zone with midzonal involvement in many of the same animals (Figure 9). Nuclear chromatin clumping with early karyorrhexis was occasionally observed and less frequently noted were single necrotic cells characterized by their dark appearance and by being dislodged from their normal position. Vacuolar degeneration was the most prominent change and was characteristic of either water accumulation with distortion of endoplasmic reticulum following cellular membrane damage, markedly dilated mitochondria due to a primary injury to mitochondria, or lipidosis, a result of an overload of metabolic pathways.

Table 4 Statistical Analysis of Select Nonneoplastic Lesions in Male Rats in the Three-month Feed Study of (+)-Usnic Acid^a^

| 0 ppm | 30 ppm (2.5)^b^ | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 720 ppm (60)
Liver
Hepatocellular Degeneration
Overall rate^c^ | 1/10 (10.0%) | 0/10 (0.0%) | 3/10 (30.0%) | 4/10 (40.0%) | 10/10 (100.0%) | 10/10 (100.0%)
Terminal rate^d^ | 1/10 (10.0%) | 0/10 (0.0%) | 3/10 (30.0%) | 4/10 (40.0%) | 10/10 (100.0%) | 10/10 (100.0%)
CAFÉ p value^e^ | p ≤ 0.001 | p = 0.500N | p = 0.291 | p = 0.152 | p ≤ 0.001 | p ≤ 0.001
Average severity^f^ | 1.0 | –^g^ | 1.0 | 1.3 | 1.9 | 3.6
Inflammation
Overall rate | 0/10 (0.0%) | 1/10 (10.0%) | 3/10 (30.0%) | 3/10 (30.0%) | 8/10 (80.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | 1/10 (10.0%) | 3/10 (30.0%) | 3/10 (30.0%) | 8/10 (80.0%) | 10/10 (100.0%)
CAFÉ p value | p ≤ 0.001 | p = 0.500 | p = 0.105 | p = 0.105 | p ≤ 0.001 | p ≤ 0.001
Average severity | – | 1.0 | 1.0 | 1.0 | 1.3 | 1.3
Kidney
Hydronephrosis
Overall rate | 0/10 (0%) | – | – | 0/10 (0.0%) | 2/10 (20%) | 10/10 (100%)
Terminal rate | 0/10 (0%) | – | – | 0/10 (0.0%) | 2/10 (20%) | 10/10 (100%)
CAFÉ p value | p = 0.001 | – | – | – | p = 0.237 | p = 0.016
Average severity | – | – | – | – | 1.5 | 1.4

^a^ Complete details of the dosing schedule are given in the methods section.

^b^ Denotes target dose as mg (+)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^d^ Observed incidence at terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with exposure. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N. Significant p values are bolded.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

^g^ Indicates no data were collected.

Figure 5

Section of the Liver from 0 ppm F344/N Nctr Rats from the Three-month Feed Study of (+)-Usnic Acid (H&E)

H&E = hematoxylin and eosin stain.

Figure 6

Section of the Liver from 120 ppm F344/N Nctr Rats from the Three-month Feed Study of (+)-Usnic Acid (H&E)

H&E = hematoxylin and eosin stain.

Figure 7

Section of the Liver from 360 ppm F344/N Nctr Rats from the Three-month Feed Study of (+)-Usnic Acid (H&E)

H&E = hematoxylin and eosin stain.

Figure 8

Section of the Liver from 720 ppm F344/N Nctr Rats from the Three-month Feed Study of (+)-Usnic Acid (H&E)

H&E = hematoxylin and eosin stain.

Figure 9

Section of the Liver from a 720 ppm F344/N Nctr Rat from the Three-month Feed Study of (+)-Usnic Acid (H&E)

Extended view to show centrilobular location of degeneration (upper right) with minimal damage to the periportal region (lower left).

H&E = hematoxylin and eosin stain.

Hepatic inflammation was significantly increased in the males exposed to 360 and 720 ppm relative to the control group (Table 4[REMOVED REF FIELD]). Also, hydronephrosis (dilatation of the renal pelvis and loss of medullary tissue) had a higher incidence only in males exposed to 720 ppm. These tissues were examined microscopically in progressively lower exposure levels until a no-observed-adverse-effect level (NOAEL) was reached at 120 ppm.

There was a test article-related statistically significant decrease in the proportion of females cycling at 720 ppm (7/10 versus 10/10 in other groups, including control groups) that was due to extended diestrus (Table G-2). Five females in the 720 ppm group, including four females that were not cycling, displayed extended diestrus (5 or more consecutive days in diestrus) compared to none in the other groups, including controls, which translated to a significant increase in the percentage of days in diestrus at 720 ppm compared to controls (69.4% versus 57.5%). As a result of the extended diestrus, the percentage of days in proestrus was decreased at 720 ppm compared to the control female rats although it did not reach statistical significance (means of 13.1% and 19.4%, respectively). The percentage of days in estrus was similarly decreased without statistical significance at 720 ppm compared to control female rats (means of 13.8% and 19.4%, respectively). The percentage of days in metestrus was similar across groups. The mean cycle length in cycling females was significantly increased in the 720 ppm group compared to the control group.

In the male rats, exposure to 720 ppm (+)-usnic acid resulted in significantly increased absolute and/or relative weights of the testes and epididymides, but sperm parameters were not significantly altered (see Table E-1 and Table G-1).

## Mice

### Survival

Disposition data and survival probabilities for the male and female B6C3F1/Nctr mice are shown in Table 5. Except for one female mouse, which died prematurely due to a cage incident, all mice in all exposure groups survived to terminal sacrifice. No further statistical analysis was performed because there were no premature removals due to exposure.

Table 5 Survival, Disposition, and Body Weights of Mice in the Three-month Feed Study of (+)-Usnic Acid

Parameter^a^ | 0 ppm | 15 ppm (2.5)^b^ | 30 ppm (5) | 60 ppm (10) | 180 ppm (30) | 360 ppm (60)
Male
Mice Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 0
Moribund | 0 | 0 | 0 | 0 | 0 | 0
Mice Surviving to Study Termination | 10 | 10 | 10 | 10 | 10 | 10
Probability of Survival to End of Study | 100% | 100% | 100% | 100% | 100% | 100%
Mean Survival (Days)^c^ | 94 | 94 | 94 | 94 | 94 | 94
Initial Body Weight (g)^d^ | 22.4 ± 0.5 | 22.0 ± 0.6 | 22.1 ± 0.7 | 22.2 ± 0.6 | 22.2 ± 0.5 | 21.5 ± 0.4
Final Body Weight (g)^d^ | 30.7 ± 0.7 | 30.9 ± 0.5 | 30.6 ± 0.5 | 31.0 ± 0.8 | 29.8 ± 0.7 | 29.5 ± 0.4
Change in Body Weight (g) | 8.3 | 8.9 | 8.5 | 8.8 | 7.6 | 8.0
Final Weight as % of Controls | –^e^ | 100.7 | 99.7 | 101.0 | 97.1 | 96.1
Observed Dose (mg/kg/day)^f^ | – | 4.04 ± 0.15 | 8.25 ± 0.46 | 15.58 ± 0.36 | 46.82 ± 0.96 | 98.88 ± 3.19
Female
Mice Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Accidental Deaths | 0 | 0 | 1 | 0 | 0 | 0
Natural Deaths | 0 | 0 | 0 | 0 | 0 | 0
Moribund | 0 | 0 | 0 | 0 | 0 | 0
Mice Surviving to Study Termination | 10 | 10 | 9 | 10 | 10 | 10
Probability of Survival to End of Study | 100% | 100% | 90% | 100% | 100% | 100%
Mean Survival (Days) | 94 | 94 | 86.4 | 94 | 94 | 94
Initial Body Weight (g) | 17.8 ± 0.2 | 18.1 ± 0.3 | 18.3 ± 0.3 | 17.3 ± 0.3 | 18.0 ± 0.2 | 18.5 ± 0.3
Final Body Weight (g) | 24.6 ± 0.4 | 24.3 ± 0.4 | 24.1 ± 0.6 | 23.8 ± 0.4 | 24.6 ± 0.3 | 24.4 ± 0.4
Change in Body Weight (g) | 6.8 | 6.2 | 5.8 | 6.5 | 6.6 | 5.9
Final Weight as % of Controls | – | 98.8 | 98.0 | 96.7 | 100.0 | 99.2
Observed Dose (mg/kg/day) | – | 5.38 ± 0.20 | 9.84 ± 0.28 | 20.92 ± 0.80 | 58.04 ± 1.59 | 124.37 ± 2.04

^a^ Complete details of the dosing schedule are given in the methods section.

^b^ Denotes target dose as mg (+)-usnic acid per kg/day, calculated from historical body weight and feed consumption data.

^c^ Animals were assigned to the study for 94 days but were exposed to dosed feed for 90 days.

^d^ Body weight (g) as mean ± standard error.

^e^ Not applicable.

^f^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving mice in each exposure group. Observed feed consumption values do not correct for spillage. Data presented as mean ± standard error for the 13 weekly values.

### Body and Organ Weight Analysis

Summary statistics of body weight by week are given in Appendix D and body weight growth curves are shown in Figure 10. The effect of (+)-usnic acid exposure on body weight was of interest because human exposure is primarily due to its use as a weight-loss agent. For males, there was a significant exposure effect (p = 0.001). For both females and males, there were significant effects for study week (p ≤ 0.001) and covariate baseline body weight (p ≤ 0.001). Weekly pairwise comparisons of each exposure group to the control group are also presented in detail in Appendix D. For female B6C3F1/Nctr mice, there was a negative overall dose trend and a negative dose trend at weeks 5 through 8. There was a significant overall difference from the control group for the 360 ppm group with the treated group showing lower body weights (97.8%, p = 0.044) compared to the control group. The 360 ppm group also had a lower mean weight compared to controls at week 6 (p ≤ 0.05). The 30 ppm group had a lower mean weight compared to controls at weeks 5 and 6 (p ≤ 0.05). For male B6C3F1/Nctr mice, there was a negative overall dose trend and a negative dose trend at weeks 3 through 9 and at week 11.

Figure 10

Growth Curves for Male and Female Mice Exposed to (+)-Usnic Acid in Feed for Three Months

Plotted as mean body weights of each exposure group.

A full statistical analysis of the effects of 3-month exposure of B6C3F1/Nctr mice exposed to (+)-usnic acid on organ weights is presented in Appendix E. Relative weights, calculated as organ weight (mg) to receiving weight (g), were also evaluated. In females, there were significant positive overall trends for absolute and relative liver weights (p ≤ 0.001), and there was a significant difference between the control group and the 360 ppm exposure group with the treated group showing higher mean liver weights (21.0%, p ≤ 0.01 and 19.3% greater, p ≤ 0.001 for absolute and relative, respectively) compared to the control group. In males, there was a significant positive overall trend for absolute and relative liver weights (p ≤ 0.05 and p ≤ 0.001, respectively) and compared to the control group, there were significant differences for the 180 ppm and 360 ppm exposure groups in relative liver weights with the treated groups showing higher mean weights (9.8% greater, p ≤ 0.05 and 17.7% greater, p ≤ 0.001, respectively).

The body weight data and feed consumption data (Appendix D and Appendix F) were used to estimate the actual dose of (+)-usnic acid in each exposure group on days 28, 46, and 88 of the study. The data are shown in Table F-6 and summarized in Table 5. In contrast to the rats, the mice appeared to consume more feed than expected so that the observed (+)-usnic acid exposure was considerably greater than the target dose for all exposure groups. However, the observed feed consumption, which varied considerably between individual mice, included feed lost to spillage so that the actual feed consumption, and hence ingested dose, would be expected to be less. Because of this, exposure levels for these studies are based on the ppm concentration of (+)-usnic acid in feed and target mg/kg/day values are provided as an approximate comparison to human exposure levels.

### Pathology and Statistical Analyses

There were no exposure-related histopathological findings noted in either male or female B6C3F1/Nctr mice. All lesions that were coded were considered spontaneous background changes (Appendix A). However, as shown in Appendix C, serum creatinine, alanine aminotransferase, alkaline phosphatase, and BUN were moderately elevated in the 180 and/or 360 ppm exposure groups from male, but not female, B6C3F1/Nctr mice. There were no significant differences in reproductive toxicity parameters observed in either male or female mice (see Appendix G).

## Genetic Toxicology

Exposure to (+)-usnic acid for 14 days significantly increased the incidence of micronuclei in erythrocytes or reticulocytes from both male and female B6C3F1/Nctr mice (Appendix B).