# Introduction

Figure 1

(+)-Usnic Acid (CASRN 7562-61-0; Chemical Formula: C_18_H_16_O_7_; Molecular Weight: 344.32)

Synonyms: 2,6-diacetyl-7,9-dihydroxy-8,9b(R)-dimethyldibenzofuran-1,3(2H,9bH)-dione; (d)-usnic acid; usneine; usninic acid; usniacin. Trade names: Usnea extract, usnic acid.

## Chemical and Physical Properties

2,6-diacetyl-7,9-dihydroxy-8,9b(R)-dimethyldibenzofuran-1, 3(2H,9bH)-dione ((+)-Usnic acid), CASRN 7562-61-0, is a bright-yellow dibenzofuran compound, which occurs naturally as a secondary metabolite of lichens of the Usnea genus and several other genera.^1^ While both the (+)- and (−)-usnic acid enantiomers (also denoted as d and l enantiomers, respectively) have been isolated from lichens, the (+)-usnic acid enantiomer usually predominates in Cladina, Evernia, Flavocetraria, Lecanora, Lobaria, Melanelia, Nephroma, Parmelia, Ramalina, Usnea, and Xanthoparmelia species.^1-7^ (−)-Usnic acid (CASRN 6159-66-6) predominates in most species of Alectoria, Cladonia, Rhizoplaca, and several other genera.^1^ The two enantiomers differ in their R or S projection of the angular -CH_3_ group at the chiral 9b position. Racemic mixtures of (+)- and (−)-usnic acid enantiomers are listed under the CASRN 125-46-2. There has been some controversy over the correct absolute enantiomeric structure of (+)- or (−)-usnic acid.^8^ Huneck and collaborators assigned the R configuration to the chiral methyl group of (+)-usnic acid by using x-ray crystallography to determine the structure of the (−)-α-phenylalanine derivative^9^ and this configuration has been confirmed by others.^10^ However, the structure of (+)-usnic acid frequently appears in the literature drawn as the S configuration of (−)-usnic acid.^8^ Authentic (+)-usnic acid isolated from Usnea lichens is dextrorotatory with a specific rotation of +478° [c 0.2%, CHCl_3_, (deg mL) (g dm)-1].^8^ It has a melting point of 204°C and is practically insoluble in water, moderately soluble in acetone and ethyl acetate, and more soluble in tetrahydrofuran and furfural.^11,12^ The sodium dihydrate salt of usnic acid is slightly soluble in water.^11^ (+)-Usnic acid can be chemically synthesized from methylphloroacetophenone by oxidative coupling followed by hydrolysis in sulfuric acid.^13^ In 1969, Taguchi and coworkers^14^ confirmed that methylphloroacetophenone, which is produced from acetyl CoA, was also an intermediate in the biosynthesis of both enantiomers of usnic acid in lichens. (+)-Usnic acid absorbs light predominantly in the UVB (280–315 nm) region with a peak extinction coefficient at 283 nm of 45,000 M^-1^cm^-1^, which has led investigators to suggest that one biological function of (+)-usnic acid is to protect the lichen from the high levels of ultraviolet radiation that is ubiquitous to many of the environments where lichens thrive.^15^

Of the three hydroxyl groups present in the usnic acid molecule, the enolic hydroxyl at the 1 position has the strongest acidic character (pKa 4.4) due to the inductive effect of the keto groups at positions 3 and 11, whereas the hydroxyl groups at positions 7 and 9 are less acidic with pKa values of 8.8 and 10.7, respectively.^4^ (+)-Usnic acid is highly lipophilic in both neutral and anionic forms due to its β-triketone groups, which absorb the negative charge of the anion by resonance stabilization.^16^ This lipophilicity of usnic acid and the usniate anion allows (+)-usnic acid to behave as a membrane uncoupler as is described in the Toxicity section of this report.

## Production, Use, and Human Exposure

Because of usnic acid’s bright-yellow color, usnic acid-containing lichens were extensively used as a fabric dye for many years in Europe prior to the advent of synthetic aniline dyes.^17^ Racemic (+/−)-usnic acid was first isolated from Usnea lichens in 1843,^4^ and was first chemically synthesized in 1956.^13^ Currently, commercial preparations of (+)-usnic acid are purified from dried wild-collected lichen or from segments of thalli of Usnea and Ramalina species grown in tissue culture.^18^ An alternative synthesis method has been reported for (+/−)-usnic acid.^19^ This method involves a two-step procedure that uses commercially available phloracetophenone—methylated with iodomethane to form trihydroxyacetophenone which is oxidized to usnic acid with horseradish peroxidase. (+)-Usnic acid can be purified from racemic mixtures by chiral chromatography.^20,21^

(+)-Usnic acid has been formulated into creams, toothpaste, mouthwash, deodorants, antibiotic ointments, sunscreen products, and antimicrobial preparations at concentrations of 0.1%–2%.^18,22^ (−)-Usnic acid has not been produced in commercial quantities. In Italy, usnic acid has been used in vaginal creams, foot creams, powders, and hair shampoo.^23,24^ There has recently been renewed interest in (+)-usnic acid’s therapeutic potential. In the United States and Canada, (+)-usnic acid has been marketed as a “fat burner” due to its activity as a mitochondrial uncoupler.^18,25^ It has also been suggested that usnic acid could be used as a biomarker to assess pollution, because its concentration in lichens can increase with the increased exposure to toxicants.^4^ It has also been proposed that (+)-usnic acid may be of use as a sunscreen agent^15^ and as a marine antifouling agent for treating ship’s hulls as a replacement for tributyltin.^26^

## Pharmacology

### Antimicrobial Activity

Prior to the discovery of penicillin, usnic acid was under active investigation for its broad-spectrum antibiotic activities. In fact, from the mid-1940s until the end of the 1950s, most of the 64 research publications on usnic acid were related to its antimicrobial activity. During the 1980s, interest in usnic acid was renewed because of increasing multi-drug resistance caused by overuse of synthetic antibiotics.^3^ Both of the optical enantiomers of usnic acid are active against Gram-positive bacteria and mycobacteria.^4^ In subsequent years, the antibacterial properties of (+)-usnic acid have been confirmed by several researchers. In preliminary clinical trials, a mouthwash containing 1% (+)-usnic acid was administered to volunteers, and at regular intervals the samples of oral bacterial flora were examined. It was reported that the growth of Streptococcus mutans involved in the etiology of dental caries was selectively suppressed.^27^ A number of preparations containing (+)-usnic acid have been marketed.^3^ Using standardized assays, the in vitro susceptibility of pathogenic Gram-positive and anaerobic bacteria toward usnic acid has been confirmed.^4^ Usnic acid has been shown to suppress the growth of Gram-positive organisms mainly responsible for body odor.^18^ (+)-Usnic acid has been shown recently to be effective, in vitro, against Staphylococcus epidermidis, S. aureus, and S. haemolyticus with minimum inhibitory concentrations of 3.12, 12.5, and 12.5 µg/mL, respectively.^28^ In another in vitro study, (+)-usnic acid was reported to be active against many strains of Helicobacter pylori with minimum inhibitory concentrations of <2 µg/mL.^29^ (+)-Usnic acid was also found to be effective against Mycobacterium aurum.^30^ In in vitro assays, (+)-usnic acid and its salt were reported to inhibit the growth of Mycobacterium tuberculosis at relatively low concentrations.^18^ Liposomes,^31,32^ cationic polyacrylamide nanoparticles,^33^ or nanofluids^34^ containing (+)-usnic acid have been investigated as potential therapeutic agents for treating antibiotic resistant bacterial infections because encapsulation increases the potency of (+)-usnic acid. Liposomal encapsulation reduced the in vitro minimal inhibitory concentration of (+)-usnic acid against multi-drug resistant Mycobacterium tuberculosis from 31.25 to 0.98 μg/mL.^31^ However, liposomal encapsulation of (+)-usnic acid has also been shown to enhance its uptake by macrophages.^35^ While encapsulation is expected to reduce the toxicity of (+)-usnic acid, it may also reduce its bactericidal activity by an equivalent factor. A recent study by Martinelli and coworkers^36^ reported a minimum inhibitory concentration for (+)-usnic acid incorporated into carboxylated poly-L-lactide microparticles of 160 µg/mL against planktonic S. epidermidis compared to a minimum inhibitory concentration of 16 µg/mL for free (+)-usnic acid. The encapsulated preparation provided a slow release of (+)-usnic acid and was more efficient than solubilized (+)-usnic acid in inhibiting bacterial biofilm growth. Recently, (+)-usnic acid has been used as an antimicrobial additive in experimental collagen-based 3D matrices for use for tissue regeneration; these matrices allowed proliferation of osteoblasts but suppressed growth of S. aureus.^37^ (+)-Usnic acid has been used experimentally as an additive to polymethylmethacrylate surgical bone cement to inhibit bacterial biofilm formation.^38^ While relatively high concentrations of (+)-usnic acid (approximately 12% in the cement) did significantly inhibit biofilm formation by methicillin-resistant S. aureus, it also induced small changes in the material characteristic of the cement. Nevertheless, the investigators supported a potential role for (+)-usnic acid in controlling bacterial biofilm formation in bone cement.

### Antimycotic Activity

During a short-term treatment with a usnic acid salt (copper usnate), 65 patients with tinea pedis (athlete’s foot) exhibited a significant improvement in their clinical conditions.^3^ (+)-Usnic acid (25–100 µg/mL) has been reported to inhibit biofilm formation in in vitro cultures of Candida albicans, but did not inhibit its proliferation.^39^ Conversely, in another study (+)-usnic acid isolated from Ramalina farinacea and identified by infrared spectography and polarimetry was reported to inhibit growth of C. albicans and C. glabrata with minimal inhibitory concentrations of <2 µM.^40^ Also, Pires and coworkers reported that (+)-usnic acid inhibited both the planktonic and biofilm growth of C. orthopsilosis and C. parapsilosis, with minimal fungicidal concentrations of 125 and 250 µg/mL, respectively, for the two species.^41^

### Antiprotozoal Activity

(−)-Usnic acid exhibited significant inhibitory effects against the pathogenic protozoan Trichomonas vaginalis at comparatively lower concentrations than metronidazole,^42^ whereas (+)-usnic acid isolated from Chilean lichens showed leishmanicidal properties in both in vitro and in vivo studies; intralesional administration produced a reduction in lesion weight as well as parasite body burden.^43^ In a recent Chinese study,^44^ (+)-usnic acid was shown to be active against the toxoplasmosis parasite, Toxoplasma gondii in an in vitro assay at a dose range of 0.25–4.0 µM and increased the survival time of mice infected with T. gondii when given at oral doses of 10 or 20 mg/kg body weight/day (mg/kg/day) in a 20-day exposure study. When encapsulated in liposomes and given at an oral dose of 10 mg/kg/day (+)-usnic acid improved survival to a greater extent than either dose given in unencapsulated form. (+)-Usnic acid was also found to be active against the malarial parasites, Plasmodium berghei and Plasmodium falciparum^45^; reported median inhibitory concentration (IC_50_) values were 2.3 and 45 μM, respectively, for the liver stage of P. berghei and the blood stage of P. falciparum, and toxicity was associated with inhibition of fatty acid metabolism.

### Antiviral Activity

In a cancer chemoprevention assay, (+)-usnic acid isolated from Usnea longissima was found to be significantly effective against teleocidin b4-induced Epstein-Barr virus with a median effective dose (ED_5O_) of 1.0 µg/mL.^46^ (+)-Usnic acid also inhibited the cytopathic effects of herpes simplex type 1 and polio type 1 viruses in infected African green monkey kidney cells.^4^ In a clinical trial, the effect of an intravaginal formulation containing (+)-usnic acid and zinc sulfate as an adjuvant therapy on radiosurgical treatment was evaluated in 100 women with genital infections of human papilloma virus. The treatment significantly improved the time of re-epithelization 1 month after the radio surgery.^47^

### Insecticidal Activity

(+)-Usnic acid showed strong larvicidal activity and caused 100% mortality in the third to fourth larval stages of Culex pipiens (house mosquito) at 24 hours at the doses of 5 and 10 ppm.^48^ (+)-Usnic acid was also reported to be larvicidal against the second and third instar larvae of the mosquito Culiseta longiareolata with median lethal dose (LD_50_) and 90% lethal dose (LD_90_) values of 0.48 and 1.54 ppm, respectively.^49^

### Antiproliferative Activity

(+)-Usnic acid caused moderate inhibition in the murine P388 leukemia assay, and also exhibited cytotoxic activity against cultured L1210 cells; it was inferred that the p-tri-ketone moiety was essential for optimum activity.^50^ On the other hand, (+)-usnic acid (50 µg/mL) reduced the cell counts of leukemic (K-562) and endometrial (Ishikawa and HEC-50) carcinoma cell cultures.^51,52^ (+)-Usnic acid exhibited cytotoxic activity against human keratinocyte cell cultures.^53^ Recent studies reviewed by Kapoor^54^ have demonstrated that (+)-usnic acid is cytotoxic to cultured cancer cells derived from many different types of tumors. For example, Bačkorová and coworkers reported IC_50_ values ranging from 48 to 178 µM for nine cell lines,^55^ with the cytotoxicity being related to loss of mitochondrial membrane potential.^56^ Sahu and coworkers reported a median lethal concentration (LC_50_) value of 30 µM for a human hepatoma (HepG2) cell line,^57^ and Brisdelli and coworkers reported IC_50_ values of 17.7, 23.7, and 75.7 µM for HCT116, HeLa, and MCF-7 cells, respectively.^58^ Singh and coworkers reported concentrations of 10–100 µM (+)-usnic acid induced cell cycle arrest, mitochondrial membrane depolarization, and apoptosis in lung carcinoma, A549 cells.^59^ Chen and coworkers demonstrated that (+)-usnic acid exposure induced both apoptosis and autophagy in HepG2 cells.^60^ However, none of these studies compared the toxicity of (+)-usnic acid in cancer cells with that in normal cells in primary culture or in vivo. Recently, Bruno and coworkers reported that (+)-usnic acid gave an IC_50_ value of 24 µg/mL for spontaneously transformed human keratinocytes after 24 hours in culture.^61^ (+)-Usnic acid has also been reported to inhibit migration and invasive activity of A549 lung carcinoma cells in vitro by a mechanism that involved downregulation of AP-1 mediated pathways and that was additive to the inhibitory action of the EGF-receptor antibody drug cetuximab.^62^ In another study, Einarsdóttir and coworkers^63^ demonstrated that both (+)- and (−)-usnic acid were equally potent in inhibiting the proliferation and cell size of two carcinoma cell lines, T-47D (mammary) and Capan-2 (pancreatic cancer), by mechanisms that involved disruption of the cell’s inner mitochondrial membrane potential. (+)-Usnic acid has been shown to strongly inhibit angiogenesis in both chick embryo chorioallantoic membrane and mouse corneal angiogenesis assays.^64^ In the same study, it also inhibited growth of implanted Bcap-37 breast tumors in a mouse xenograft model.

### Anti-inflammatory Activity

In an acute rat paw edema and a chronic rat cotton pellet assay at 100 mg/kg oral dose level, the anti-inflammatory action of (+)-usnic acid was comparable to ibuprofen at the same dose level.^65^ Pretreatment (50 or 100 mg/kg oral gavage for 5 days) with (+)-usnic acid has also been shown to protect mice from lipopolysaccharide (LPS)-induced inflammatory lung injury^66^ and to downregulate nuclear factor-κB-dependent tumor necrosis factor-α and inducible nitric oxide synthase expression in LPS-stimulated macrophages.^67^ (+)-Usnic acid has also been reported to accelerate wound-healing in rat and mouse in vivo wound closure assays.^61^

### Analgesic and Antipyretic Activity

The analgesic and antipyretic effects of (+/−)-usnic acid purified from Usnea diffracta were evaluated in two mouse studies.^68^ At 100 mg/kg oral dose level, usnic acid exhibited a significant analgesic effect as indicated by an acetic acid-induced writhing test and a tail pressure test. At oral dose levels up to 300 mg/kg, usnic acid also expressed significant antipyretic activity determined through LPS-induced hyperthermia.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

The pharmacokinetics of (+)-usnic acid were studied in rabbits following intravenous or oral administration of doses of 5 and 20 mg/kg body weight, respectively.^69^ Plasma usnic acid levels following intravenous administration showed a tri-exponential elimination with a terminal half-life of 10.7 ± 4.6 hours. The volume of distribution of the central compartment and systemic clearance was 43.9 ± 21.3 mL/kg and 12.2 ± 3.0 mL/hr/kg, respectively. Peak plasma level (C_max_) of 32.5 ± 6.8 µg/mL was achieved in 12.2 ± 3.8 hours (t_max_). The mean absolute bioavailability of (+)-usnic acid following oral administration was 77.8%.^70^ In rats treated intraperitoneally (i.p.) with 25 mg/kg (+)-usnic acid, the usnic acid accumulated in the liver and lungs at levels similar to plasma concentrations, but accumulated at lower concentrations in brain, fat, testis, and other organs.^70^ A protein binding of (+)-usnic acid in rabbit plasma and bovine serum albumin revealed that (+)-usnic acid was extensively bound to protein with approximately 99.2% in bound form.^70^ A tissue disposition study in rats following 25 mg/kg (i.p.) administration showed that (+)-usnic acid distributed into various tissues and tissue levels were high in lung, liver, and blood with mean tissue/plasma ratios of 1.777, 1.503, and 1.192, respectively.^70^ (+)-Usnic acid was reported to penetrate porcine skin in vitro with significant amounts accumulating in the stratum corneum and dermis layers after 12 hours of exposure.^71^

### In Vitro

The in vitro metabolism of (+)-usnic acid was investigated using human plasma, hepatocytes, and liver subcellular fractions.^72^ To identify metabolites, (+)-usnic acid was incubated in human liver S9 fractions and samples were analyzed by LC/MS (liquid chromatograph/mass spectrometry) ion chromatograms. Various metabolites, including three oxidized metabolites and two glucuronide conjugates, were identified. Two of the oxidation products were regioisomeric hydroxy ketones and were not differentiated by LC/MS. A third monohydroxylated metabolite was also identified but not characterized. The two isomeric glucuronides were conjugates of parent (+)-usnic acid. In this in vitro study, the authors also reported that the half-life of (+)-usnic acid in human liver microsomes was 19.3 minutes with an intrinsic clearance of 45.24 mL/min/kg. This half-life predicted a human hepatic clearance of 13.86 mL/min/kg. Phase I metabolizing enzymes (cytochrome P450 [CYP] isoforms) involved in oxidative metabolism of (+)-usnic acid were also investigated using human liver microsomes pre-incubated with (+)-usnic acid and several CYP inhibitors.^72^ The inhibitors, used to infer the CYP isoforms responsible for catalyzing the turnover of (+)-usnic acid, included furafylline (CYP1A2), thiotepa (CYP2B6), quercetin (CYP2C8), sulfaphenazole (CYP2C9), (s)-(+)–3-benzylnirvanol (CYP2C19), quinidine (CYP2D6), and ketoconazole (CYP3A4/5). Among the inhibitors investigated, only furafylline, the inhibitor of CYP1A2, showed the effect on the turnover rate of (+)-usnic acid by increasing its half-life tenfold. This observation suggested that the oxidative metabolism of usnic acid was probably mediated by CYP1A2. This study suggested that (+)-usnic acid was a weak inhibitor of CYP2D6, a potent inhibitor of CYP2C19 and CYP2C9, and a less potent inhibitor of CYP2C8 and CYP2C18. Assays using 12 recombinant human UDP-glucuronosyltransferase (UGT) isoforms suggested that UGT1A1 and UGT1A3 played a major role in glucuronidating (+)-usnic acid, with a minor contribution of UGT1A8.^72^

## Toxicity

### Experimental Animals

Irrespective of a long history of usnic acid-containing products, only a few animal studies had been conducted to evaluate the clinical safety of (+)-usnic acid when it was nominated for evaluation by NTP; no systemic subchronic and chronic general toxicity studies had been conducted; and the conduct and quality of some of the available studies were questionable.^18^ LD_50_ values for usnic acid (enantiomer not specified) were reported as 25, 75, and 838 mg/kg for mice exposed via intravenous, subcutaneous, and oral routes, respectively, and 500 mg/kg for rabbits exposed orally.^18^ More recent studies of mice have reported LD_50_ values for oral and i.p. exposure to (+)-usnic acid of 388 and 75 mg/kg, respectively.^73,74^

Acute toxicity studies of (+)-usnic acid have been reported for both animals and plants. In several experimental animal or wild animal species—such as guinea pigs, mice, rats, domestic sheep, cow elk, and mosquitoes—either general toxicity or organ-specific toxicity, or both, have been reported. In female guinea pigs with tuberculosis, subcutaneous injection of usnic acid (20 mg per animal for 6 days, followed by 10 mg per animal for 24 days; enantiomer not specified) caused a slight weight loss in the first week and a significant inhibition of weight gain during the next 3 weeks.^75^ Even after the discontinuation of usnic acid, weight gain was still reduced 44%–68% for at least 2 weeks. This report was the first to show that usnic acid could cause weight loss with the possibility of general toxicity, although this possibility was largely ignored in the ensuing decades. Of note, no apparent organ-specific toxicities in the liver, spleen, or lung were observed in this report, and no apparent therapeutic effects were observed.^75^ In healthy male Swiss mice, treatment with (+)-usnic acid i.p. at 15 mg/kg for 15 days caused no apparent general toxicity, as evidenced by the negative observations in clinical signs or changes of body weight.^76,77^ However, strong hepatotoxicity, including elevated serum transaminase activity and extensive liver necrosis, was observed. No toxicity in other organs, such as kidney and spleen, was detected in the study. A similar pattern of toxicity was also revealed in the tumor-bearing mice in the study.^76,77^ In male Wistar albino rats, (+)-usnic acid (i.p., 50 or 200 mg/kg for 5 days) induced remarkable swelling of the liver mitochondria and endoplasmic reticulum assessed by electron microscopy, although no changes in serum transaminase activity were observed, suggesting that only mild hepatotoxicity occurred.^78^ Conversely, a more recent study that administered (+)-usnic acid at 100, 200, and 240 mg/kg to male Wistar rats via oral gavage for 8 days observed significantly elevated alanine aminotransferase and total bilirubin after 3 and 6 days in the 100 and 200 mg/kg groups and hepatic degeneration in the 200 mg/kg group, but not in the 100 mg/kg group. Less than 50% of the 240 mg/kg dosed group survived the experiment.^79^ Another study investigated potential cardiotoxicity in female rats receiving 30 or 100 mg (+)-usnic acid in methylcellulose/kg/day via oral gavage for 14 days.^80^ Neither dose caused alterations in blood chemistry parameters but cytoplasmic rarefaction of myocardium in conjunction with mitochondrial swelling and increased prohibitin expression were observed in animals from the 100 mg/kg/day group.

Feeding domestic sheep with (+)-usnic acid of 323–776 mg/kg/day for a maximum of 9 days induced several clinical signs such as lethargy and anorexia, or even death, with the estimated median toxic dose between 485 and 647 mg/kg/day.^81^ Other toxicity indices, such as serum lactate dehydrogenase, aspartate aminotransferase, and creatine kinase, were also increased. A complete postmortem examination revealed that pathological changes occurred exclusively in the skeletal muscle.^82^ This observation contrasts sharply with mice, rats, and humans, in which the liver is considered to be the organ most vulnerable with usnic acid insults. Usnic acid is also the assumed toxicant associated with some 400–500 cow elk deaths that occurred in Wyoming in 2004.^82,83^ Necropsy revealed extensive muscle damage, such as muscle pallor and streaking, particularly in the semitendinosus, semimembranosus, and pelvic limbs. Histological examination showed necrosis, rupture, inflammation, and degeneration of myofiber. However, a causative relation between muscle damage and usnic acid exposure was not established.

Usnic acid also acts as a strong toxicant toward certain insects, such as mosquitoes. It has been reported that both (+)- and (−)-usnic acids (5 and 10 ppm) killed all the larvae of certain species of mosquitoes during their third and fourth stages with similar potency, suggesting that they might be developed as a novel natural insecticide.^48^ In addition to the toxicity toward animals, usnic acid displays phytotoxicity as well. It exerts toxic effects on the growth of onion and lettuce, possibly by inhibition of plant p-hydroxyphenylpyruvate dioxygenase, indicating the potential usage as an herbicide.^84^ In another study, (+)-usnic acid added to cultures of Nicotiana tabacum protoplasts reduced protoplast viability at concentrations of 5–200 µg/mL.^51^ (+)-Usnic acid has also been shown to inhibit growth of the free living alga, Scenedesmus quadricauda, concurrent with increased oxidative damage and decreased chlorophyll production.^85^

#### Subchronic Toxicity Studies

No subchronic animal studies were found in the literature.

#### Chronic Toxicity Studies

Extensive library searches (Frankos,^18^ updated in 2017) did not provide any information about chronic toxicity studies.

### In Vitro

(+)-Usnic acid is highly lipophilic in both neutral and anionic forms because it is able to absorb the negative charge of the usnate anion by resonance stabilization over its β-triketone groups (Figure 2),^16^ which allows (+)-usnic acid to act as a membrane uncoupler in a manner similar to that of 2,4-dinitrophenol (Figure 2).^25,51,86^ According to chemiosmotic theory, such molecules easily diffuse through biological membranes in both their charged and neutral forms, resulting in the breakdown or uncoupling of ion gradients.^87^ For example, (+)-usnic acid can pass through the inner mitochondrial membranes by passive diffusion into the matrix where it is ionized, releasing a proton into the matrix. The resulting usnate anion can then diffuse back into the inter-membrane space where it binds to a proton on the acidic side of the inner membrane proton gradient to re-form (+)-usnic acid, which can then diffuse back into the matrix.

Figure 2

Structures of the Monoanionic Forms of (+)-Usnic Acid and 2,4-Dinitrophenol Showing the Resonance Stabilization of Their Negative Charges by Delocalization of Their π Orbital Electrons (Dashed Lines) as Described by Mitchell^87^

The resulting cycle (Figure 3) causes proton leakage that eventually can dissipate the proton gradient across the inner membrane, disrupting the tight coupling between electron transport and adenosine 5’-triphosphate (ATP) synthesis. This mitochondrial uncoupling activity of (+)-usnic acid has been demonstrated in vitro in several studies.^78,88-90^

Figure 3

Mechanism of Mitochondrial Uncoupling as Originally Proposed by Mitchell^87^

Chemicals with membrane uncoupling activity, such as UA, are lipophilic and can diffuse through biological membranes in both their ionized and unionized forms; they can therefore transport protons across the inner mitochondrial membrane by passive diffusion, analogous to mitochondrial UCPs, resulting in a reduced proton gradient to drive ATP synthesis and the generation of heat.

H^+^ = proton; ATP = adenosine triphosphate; ADP = adenosine diphosphate; Pi = inorganic phosphate; UAH = (+)-usnic acid; UA = usnate anion; UCP = uncoupling protein.

Uncoupling of oxidative phosphorylation by (+)-usnic acid was confirmed in mouse liver mitochondria by Abo-Khatwa et al.^88^ Concentrations as low as 0.75 µM (+)-usnic acid decreased the phosphate/oxygen ratio dramatically, without inhibition of oxygen consumption. Stimulation of oxygen consumption by (+)-usnic acid was observed in the presence of the ATP synthase inhibitor oligomycin, confirming that usnic acid was acting to uncouple oxidative phosphorylation. Interestingly, approximately 10× the concentration of the classic uncoupler, 2,4-dinitrophenol, was required to reproduce the level of uncoupling produced by the usnic acid exposure. In observations similar to those of Johnson and Feldott,^91^ Abo-Khatwa et al.^88^ reported inhibition of mitochondrial oxygen consumption at (+)-usnic acid concentrations above 1 µM, again suggesting adverse effects on mitochondrial function not limited to uncoupling. They noted that usnic acid possessed physical properties like that of a “membrane disruptor,” consistent with its uncoupling actions. Sahu and coworkers^57^ recently reported that (+)-usnic acid was cytotoxic to cultured human hepatoblastoma, HepG2 cells, with a 24-hour LC_50_ value of 30 µM. These HepG2 cells exhibited a statistically significant reduction in mitochondrial membrane potential and increased oxidative stress when exposed to (+)-usnic acid concentrations of 20, 50, or 100 µM, but not at lower concentrations.

Pramyothin et al.^78^ reported, however, that in isolated rat liver mitochondria, (+)-usnic acid concentrations as low as 0.3 µM could significantly increase ATPase activity and oxygen consumption. The same study showed that in isolated rat hepatocytes (+)-usnic acid also stimulated markers of lipid peroxidation, but that much higher concentrations were required (100 µM). These effects have been confirmed and extended by other studies,^89^ which used mouse hepatocytes. Unlike classic mitochondrial membrane uncouplers such as 2,4-dinitrophenol, usnic acid stimulates the production of reactive oxygen species while also depleting ATP levels.^89^ The resulting lipid peroxidation and oxidative damage causes cytotoxicity and cell death. (+)-Usnic acid was recently shown to decrease ATP concentrations in perfused livers from fasted rats^92^; hepatic ATP/ADP ratios were reported to decrease after 90 minutes perfusion from 3.24 for control media, to 1.78 or 0.62 with perfusion media containing either 5 or 10 µM (+)-usnic acid, respectively.

In addition, (+)-usnic acid causes similar permeability effects on lysosomal membranes, reducing lysosomal acidity and disrupting autophagic processes.^93^ This membrane uncoupling and disrupting action of (+)-usnic acid, which also occurs with synthetic liposomes,^32^ is thought to play a major role in (+)-usnic acid-induced hepatotoxicity. However, usnic acid also produces the same uncoupling actions on bacterial cell membranes, and this forms the basis for its antimicrobial activity.

### Humans

The idea of utilizing chemicals with mitochondrial uncoupling activity for weight loss originated in the early 1930s after it was noticed that munitions workers exposed to 2,4-dinitrophenol lost weight.^94^ Subsequently, 2,4-dinitrophenol was formulated into an anti-obesity drug, which was prescribed by some physicians or directly marketed to the public with some claims of efficacy. However, many serious side effects were also recorded, including liver, heart, and muscle toxicity and cataract formation so that, in 1938, the U.S. Food and Drug Administration (FDA) finally declared 2,4-dinitrophenol too toxic for use under any circumstances.^94^ Following this declaration, reports of 2,4-dinitrophenol misuse became less frequent. Interest in uncoupling chemicals has resurfaced primarily in the body-building community with the advent of the internet and the passage of the Dietary Supplement Health and Education Act of 1994, resulting in the clandestine trade of 2,4-dinitrophenol^95,96^ and the open marketing of usnic acid and other natural products in dietary supplements formulated for weight loss.^18^ Such formulations generally contain relatively high usnic acid concentrations, either alone or in combination with other ingredients, and their use has been reported to be associated with hepatotoxicity.

In 2000, Favreau et al.^97^ reported that seven previously healthy patients developed acute hepatitis after ingesting LipoKinetix (Syntrax, Cape Girardeau, MO) and recovered spontaneously after discontinuing its use. Subsequently, two more cases of acute hepatitis were reported after taking LipoKinetix, with one resulting in a liver transplant.^98^ LipoKinetix was a multi-ingredient product; one capsule contained 25 mg of norephedrine hydrochloride, 100 mg of (+)-usnic acid, 100 µg of 3,5-diiodothyronine, 3 mg of yohimbine hydrochloride, and 100 mg of caffeine. It was sold as a dietary supplement to promote weight loss. The manufacturer claimed that LipoKinetix “affects oxidative phosphorylation in such a way that an incredible amount of fatty acids are burned,” therefore promoting weight loss. The recommended dose of LipoKinetix was one or two capsules three times per day, which is 3–6× higher than usnic acid doses of 60–180 mg used in traditional Chinese medicine. Production and sale of LipoKinetix was terminated in 2001, although Syntrax continued to produce a product with similar ingredients, but without (+)-usnic acid, which was called AdipoKinetix.

UCP-1 (BDC Nutrition, Richmond, KY) was marketed as a weight-loss product containing 150 mg of (+)-usnic acid, 525 mg of L-carnitine, and 1,050 mg of calcium pyruvate per capsule. The recommended dose of UCP-1 was three capsules three times per day. Sanchez et al.^99^ reported the development of severe liver failure in two patients who were taking the recommended dose of UCP-1; one resulted in a liver transplant. Durazo et al.^100^ also reported one case of a healthy woman who, after taking pure (+)-usnic acid (Industrial Strength AAA Services, Frazer Park, CA) for weight loss, presented with liver failure requiring a transplant. The recommended dose of pure (+)-usnic acid from this manufacturer was 500 mg/day.

FDA has received at least 21 adverse event reports including one death attributed to weight-loss supplements containing (+)-usnic acid (LipoKinetix and UCP-1) or pure (+)-usnic acid. Twelve cases associated with hepatotoxicity appeared in the literature and are summarized in Guo et al.^25^ These cases included eight females and four males; the median age of the patients was 31 years old. Two patients required liver transplantation and the others ultimately recovered. While the total number of people who have experimented with weight-loss supplements containing (+)-usnic acid is unknown, the manufacturer of LipoKinetix has claimed to have sold over 30,000 bottles of the supplement.^101^

## Reproductive and Developmental Toxicity

In a 35-day oral study in 5- to 6-week-old male Swiss mice, no adverse effects of 200 mg/kg/day of (+)-usnic acid on the number, motility, and structure of epididymal spermatozoa were observed. Additionally, no quantitative differences in the content of testicular protein, RNA, and DNA were recorded.^102^

## Carcinogenicity

There are no reports of carcinogenic activity for either usnic acid or Usnea lichen preparations. The primary focus of this study of (+)-usnic acid is acute and subchronic toxicity rather than carcinogenesis.

## Genetic Toxicity

Many plants contain endogenous compounds that are genotoxic.^103^ Using the Ames Salmonella/microsome assay, Shibamoto and Wei^90^ tested the mutagenicity of pure (+)-usnic acid along with two other lichen constituents: physodic (5´-carboxy-3,4´-dihydroxy-5-methyl-caproyl-6´-pentyl-6-carboxy-diphenyl ether 2´,6 lactone) and physodalic acid (3´-acetoxyl-5´-carboxy-3,4´-dihydroxy-2-formyl-5,6´-dimethyl-3´-methylacetoxy-6-carboxy-diphenyl ether-2´,6-lactone) in two Salmonella typhimurium strains (TA98 and TA100) with or without S9 addition. Physodalic acid exhibited a clear dose-related mutagenicity in TA100, the tester strain; the addition of S9 mix increased mutagenicity fourfold at the high dose (400 µg/plate). In contrast, (+)-usnic and physodic acids showed no mutagenicity in tested strains, including TA98 and TA100 with or without S9 addition at the highest dose of 200 µg per plate for both chemicals.

NTP studies confirmed that (+)-usnic acid was negative in Ames tests with S. typhimurium strains TA98 and TA100 and E. coli strain WP2 uvrA (pkM101), with and without the addition of rat liver S9.^104^ Koparal and coworkers^105^ evaluated both (+)-usnic acid and (−)-usnic acid genotoxicity in human lymphocytes from two healthy male donors in vitro using the cytokinesis-blocked micronucleus (CBMN) assay. The results obtained from their study suggest that even though the number of micronuclei was higher in both usnic acid enantiomers-treated human lymphocytes in comparison to those in the control, the induction was not significant statistically. The authors concluded that both (+)- and (−)-usnic acid were nongenotoxic as shown by the absence of micronucleus induction in human lymphocytes. In another study, (+)-usnic acid was also found to be nongenotoxic in cultured human lymphocytes, inducing neither micronuclei nor chromosomal aberrations at concentrations up to 200 µg/mL in the absence of S9.^106^

Oral administration of a single dose of either 100 or 200 mg/kg usnic acid caused a slight increase in micronucleated erythrocytes in the mice 24 and 48 hours after treatment, which did not reach statistical significance and returned to control levels by 72 hours.^102^ In another study, Leandro and coworkers^107^ treated Swiss mice with 25, 50, 100, or 200 mg/kg (+)-usnic acid via oral gavage. No significant treatment-related increases in either bone marrow micronucleated erythrocyte frequency or hepatic DNA damage, evaluated using a comet assay, were noted after 24 hours. However, (+)-usnic acid did significantly increase DNA damage to V79 cells in vitro when added to the culture medium at 60 or 12 µg/mL.^107^

## Study Rationale

Informed by the adverse events described above that were first reported by Medwatch in November 2001,^18^ the Center for Food Safety and Applied Nutrition (CFSAN) of the FDA issued a warning letter^108^ on November 19, 2001, entitled “FDA Warns Consumers Not to Use the Dietary Supplement LipoKinetix,” because it had been implicated in a number of serious liver injuries. After receiving additional reports of persons who developed liver injury or liver failure while using LipoKinetix, FDA subsequently issued a strong recommendation to the manufacturer, Syntrax Innovation Inc., to withdraw the product from the market (Letter to Distributor on Hazardous Dietary Supplement LipoKinetix).^109^ However, botanical extracts of Usnea lichen species are still marketed as herbal antimicrobials.

To further understand the risk to human health of usnic acid and Usnea preparations, the Office of Dietary Supplement Programs of CFSAN nominated usnic acid to NTP for the evaluation of acute and subchronic toxicity in January 2005 (see Frankos^18^). Long-term carcinogenesis studies were not required due to the focus on acute toxicity seen in humans. The study documented in this report is a 3-month subchronic study of (+)-usnic acid, administered in feed to B6C3F1/Nctr mice and F344/N Nctr rats. It was conducted in conjunction with a 14-day range-finding study (Appendix J), which was used to set the exposure levels for these subchronic studies and correlate them to daily oral dose levels derived from observed feed consumption. A companion study of Usnea lichens containing both (+)- and (−)-usnic acid is reported on in NTP TOX 105.^110^