# Acknowledgments

This study was conducted at the U.S. Food and Drug Administration’s (FDA’s) National Center for Toxicological Research under an Interagency Agreement between FDA and the National Institute of Environmental Health Sciences (NIEHS) (AES17011). This work was supported by the Intramural Research Program (ES103316, ES103318, and ES103319) at NIEHS, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts: HHSN271201800012I, GS00Q14OADU417 (Order No. HHSN273201600015U), N01-ES-65557, and HHSN273201300010C.