# Appendix J Acute Toxicity

## J.1 Background

Acute toxicity (range-finding) studies, consisting of 2-week feed studies, were conducted as part of a National Center for Toxicological Research (NCTR) experimental study to investigate the acute toxicity of both (+)-usnic acid and Usnea lichens. This summary report focuses on the acute toxicity of (+)-usnic acid, and the effects of (+)-usnic acid on hepatic ATP concentration, which is a sensitive biomarker for mitochondrial uncoupling activity.

## J.2 Experimental Methods

Animals: F344/N Nctr rats and B6C3F1/Nctr mice were provided by the NCTR breeding colonies and allocated to the experiment at 3 weeks of age. The experimental loading was staggered so that the animals were loaded in three replicates of either one or two per dose group at weekly intervals. Loading of mice preceded loading of rats. The animals were loaded on the Multigeneration Support System (MGSS) and assigned to dose groups at 6 weeks of age. The NCTR biometry staff provided a rack configuration and exposure randomization documents to control bias. Dosing, via feed, commenced at 8 weeks of age and proceeded for 14 days. The animal numbers in each dose group are listed in Table J-1 and Table J-2 for rats and mice, respectively.

The studies were run consecutively with staggered loading between December 5, 2006, and January 2, 2007, for the B6C3F1/Nctr mice and January 2, 2007, and January 30, 2007, for the F344/N Nctr rats. The animals were weighed weekly prior to dosing, and then twice weekly (i.e., every 3 or 4 days) during the dosing period so that any dose-related changes in body weight could be closely monitored. Dosed feed was allocated weekly in weighed amounts, weighed twice weekly, and the feed remaining measured so that daily feed consumption could be monitored. Morbid animals were immediately removed from the study and euthanatized.

The animals were sacrificed by decapitation and trunk blood was collected. Tissues were examined for gross abnormalities and observed lesions were processed for histopathological evaluation. These examinations were conducted under the supervision of the study pathologist. Gross examination data were recorded. The liver, kidneys, heart, and lungs from all animals were weighed wet as soon as possible after dissection.

All protocol-specified tissues were examined grossly, removed, and preserved in 10% neutral buffered formalin except eyes and testes, which were preserved in modified Davidson's fixative. The protocol-required tissues including all gross lesions were trimmed, processed, and embedded in Formula R^®^, sectioned at approximately 5 µm, and stained with hematoxylin and eosin. Tissues were examined microscopically and, when applicable, nonneoplastic lesions were graded for severity as 1 (minimal), 2 (mild), 3 (moderate), or 4 (marked).

Test article: (+)-Usnic acid (lot # 02503HD) was blended into powdered NIH-41 autoclaved rodent diet to achieve the required (+)-usnic acid concentration.

## J.3 Results

Body weight: Exposure of male and female F344/N Nctr rats to (+)-usnic acid at doses of 1,250 and 2,500 ppm decreased body weight in both sexes (Figure J-1). These decreases were apparent within 3 days of initiating dosing. The lower doses of (+)-usnic acid did not significantly reduce body weight or body weight gain. In B6C3F1/Nctr mice (Figure J-2), exposure to 1,200 ppm (+)-usnic acid resulted in large decreases in body weight in both males and females. There were smaller decreases in body weight in both male and female mice in the 600 ppm dosed group during the first week of exposure.

Survival: Exposure to 2,500 ppm (+)-usnic acid in feed was highly toxic for both male and female F344/N Nctr rats so that all 10 animals had either died or been removed as moribund by day 9 of exposure (Figure J-3). Two female rats and one male rat in the 1,250 ppm dosed group were removed by day 10 and day 11, respectively, due to morbidity and an additional morbid female was removed on day 14. All other animals on the study survived until terminal evaluation. B6C3F1/Nctr mice appeared to be more resilient to the effects of (+)-usnic acid than rats. All mice except three in the 1,200 ppm dosed group survived until terminal evaluation. In the 1,200 ppm dosed group, which corresponded to the same target dose of 200 mg/kg/day as the rat 2,500 ppm dose, two females and one male were removed due to morbidity by days 4, 8, and 6, respectively.

Histopathological effects of 2-week exposure to (+)-usnic acid: The histopathological effects of 2-week exposure of F344/N Nctr rats and B6C3F1/Nctr mice to (+)-usnic acid are listed in Table J-3 and Table J-4, respectively. Histopathological lesions were observed in both male and female F344/N Nctr rats exposed to either 1,250 or 2,500 ppm (+)-usnic acid in feed, but not at lower doses. Histopathological lesions were observed in both male and female B6C3F1/Nctr mice exposed to 1,200 ppm (+)-usnic acid in feed and in males exposed to 600 ppm, but not at lower doses. Thymic atrophy and gonadal lesions characteristic of extreme stress were observed in both rats and mice in the high dosed groups.

Hepatocellular alteration in this 2-week range-finding study included a variety of changes associated with hepatocellular toxicity. In both species, the affected animals displayed one or more of the following changes: cell swelling as well as cell contraction, cytoplasmic vacuolization or clearing, clumping (increased densities) of organelles, and in many animals, an increased cytoplasmic eosinophilia. Nuclear chromatin clumping with early karyorrhexis was occasionally observed; less frequently noted were single necrotic cells characterized by their dark appearance and being dislodged from their normal position. These changes represent patterns of cell degeneration with differences depending on the dose of toxin and the state of metabolism in the cell at the time of injury. The lesions described are part of a cascade of factors leading to irreversible degeneration and eventually necrosis.

Atrophy characterized by a decrease in the organ size was noted involving the thymus, seminal vesicles, and uterus (mice only) and was probably associated with decreased caloric intake (feed avoidance) and stress-associated metabolic changes. All other lesions were considered spontaneous background changes.

## J.4 Adenosine 5’-Triphosphate Concentrations in Liver

Usnic acid is a known mitochondrial uncoupler and has been reported to decrease adenosine 5’-triphosphate (ATP) levels in cultured hepatocytes. As part of the 2-week range-finding study, ATP concentrations were evaluated in liver samples from both rats and mice exposed to (+)-usnic acid for 14 days.^89^

### J.4.1 Methods

Hepatic ATP concentrations were determined using ATP Bioluminescent Assay kits (Sigma-Aldrich, St. Louis, MO, #FL-AA) on a Veritas 9100 Microplate Luminometer (Turner BioSystems, Sunnydale, CA). Liver extract (5%) was prepared in 2.5% trichloroacetic acid (TCA) and neutralized with 0.1 M Tris-Acetate buffer (pH 7.75) before using in a microtiter plate for ATP estimation. The luminescence data were converted to µmoles of ATP from standard solutions run with each assay plate. SAS (version 9.2, TS level 1M0) was used to produce means, standard error values and significant differences between dose groups via a Dunnett test evaluation and a linear trend test run under the SAS General Linear Models program.

### J.4.2 Results

As shown in Table J-5, ATP concentrations in livers from both male and female F344/N Nctr rats were decreased by 2-week exposure to (+)-usnic acid. The decreases were greatest in the high dosed groups, which included moribund animals. In males, hepatic ATP content was significantly reduced in the 120, 360, 1,250, and 2,500 ppm dosed groups, but statistically significant decreases were not observed in the females despite the mean ATP content of the 1,250 dosed group being <50% of that of the control group. As shown in Table J-6, ATP concentrations in livers from both male and female B6C3F1/Nctr mice were decreased by 2-week exposure to (+)-usnic acid. The decreases were greatest in the high dosed groups, which included moribund animals. Statistically significant decreases were observed in the male 180, 600, and 1,200 ppm dosed groups and in the female 600 and 1,200 ppm dosed groups.

## J.5 Serum and Hepatic Parameters Suggesting Increased Protein and Fat Catabolism in F344/N Nctr Rats Exposed to High Concentrations of (+)-Usnic Acid

As part of these 2-week range-finding toxicity studies, serum triglyceride and cholesterol concentrations were evaluated in trunk blood samples from both male and female F344/N Nctr rats that were sacrificed following 14 days of exposure or were removed from the study due to morbidity. In addition, serum leptin concentrations were evaluated in trunk blood from female F344/N Nctr rats that were sacrificed for the toxicokinetic study (measured by RIA) (Appendix K).

Hepatic tyrosine aminotransferase activity was assayed in samples of hepatic cytosol (100,000 g supernatant) prepared from livers of the male rats that either survived to their scheduled sacrifice or were removed early due to morbidity.

Exposure to high doses of (+)-usnic acid caused a significant decrease in serum leptin concentrations in the 360 and 1,250 ppm females (Figure J-5) and a significant increase in hepatic tyrosine aminotransferase activity in the 1,250 and 2,500 ppm males (Figure J-6). These changes are indicative of increased fat and protein catabolism, respectively. Serum triglyceride concentrations were also reduced in F344/N Nctr rats that were exposed to high concentrations of (+)-usnic acid in feed for 2 weeks (Table J-7). Serum triglyceride concentrations were significantly decreased in the 2,500 ppm males and in the 1,200 and 2,500 ppm females. Serum cholesterol was significantly decreased in female but not male rats exposed to (+)-usnic acid at 2,500 ppm (Table J-7).

Table J-1 Two-week Range-finding Study for (+)-Usnic Acid in Rats

Dose^a^ | | Target Dose^b^ | Males^c^ | Females^c^
None | | 0 | 5 | 5
60 | | 5 | 5 | 5
120 | | 10 | 5 | 5
360 | | 30 | 5 | 5
1,250 | | 100 | 5 | 5
2,500 | | 200 | 5 | 5
Totals | | | 30 | 30

^a^ Doses of usnic acid are given in ppm added to feed. The animals received dosed feed for 14 days prior to sacrifice.

^b^ Approximate target dose in mg/kg/day calculated from NCTR historical mean body weight and feed consumption data.

^c^ Number of animals used.

Table J-2 Two-week Range-finding Study for (+)-Usnic Acid in Mice

Dose^a^ | Target Dose^b^ | Males^c^ | Females^c^
None | 0 | 5 | 5
30 | 5 | 5 | 5
60 | 10 | 5 | 5
180 | 30 | 5 | 5
600 | 100 | 5 | 5
1,200 | 200 | 5 | 5
Totals | | 30 | 30

^a^ Doses of usnic acid are given in ppm added to feed. The animals received dosed feed for 14 days prior to sacrifice.

^b^ Approximate target dose in mg/kg/day calculated from NCTR historical mean body weight and feed consumption data.

^c^ Number of animals used.

Table J-3 Incidence (%) of Nonneoplastic Lesions in Rats in the Two-week Study of (+)-Usnic Acid^a^

| 0 ppm | 60 ppm | 120 ppm | 360 ppm | 1,250 ppm | 2,500 ppm
Male
Liver, Cellular Alteration | 0 | 0 | 0 | 0 | 100 | 100
Thymus Atrophy | 0 | 0 | 0 | 0 | 0 | 40
Seminal Vesicle Atrophy | 0 | 0 | 20 | 0 | 100 | 80
Female
Liver, Cellular Alteration | 0 | 0 | 0 | 0 | 100 | 80
Thymus Atrophy | 0 | 0 | 0 | 0 | 0 | 20

^a^ Incidence (%) based on animals per group.

Table J-4 Incidence (%) of Nonneoplastic Lesions in Mice in the Two-week Study of (+)-Usnic Acid^a^

| 0 ppm | 30 ppm | 60 ppm | 180 ppm | 600 ppm | 1,200 ppm
Male
Liver, Cellular Alteration | 0 | 0 | 0 | 0 | 80 | 80
Thymus Atrophy | 0 | 0 | 0 | 0 | 20 | 80
Seminal Vesicle Atrophy | 0 | 0 | 0 | 0 | 20 | 80
Female
Liver, Cellular Alteration | 0 | 0 | 0 | 0 | 0 | 60
Thymus Atrophy | 0 | 0 | 0 | 0 | 0 | 20
Uterine Atrophy | 0 | 0 | 0 | 0 | 0 | 40

^a^ Incidence (%) based on animals per group.

Table J-5 Hepatic Adenosine 5’-Triphosphate Concentrations in Rats Exposed to (+)-Usnic Acid for Two Weeks^a^

| 0 ppm | 60 ppm (5)^b^ | 120 ppm (10) | 360 ppm (30) | 1,250 ppm (100) | 2,500 ppm (200)
Male
Observed Dose^c^ | 0 | 5.0 | 9.3 | 27.5 | 85.4 | 239
ATP (µmol/g) | 1.46 ± 0.03 (4)^d^ p = 0.003^e^ | 1.28 ± 0.25 (4) p = 0.486 | 0.85 ± 0.07 (3) p = 0.028 | 0.56 ± 0.06 (5) p ≤ 0.001 | 0.80 ± 0.24 (3) p = 0.018 | 0.40 ± 0.19 (2) p = 0.002
Female
Observed Dose | 0 | 5.6 | 10.5 | 30.6 | 93.1 | 182
ATP (µmol/g) | 1.09 ± 0.13 (3) p = 0.062 | 1.02 ± 0.31 (5) p = 0.688 | 0.81 ± 0.14 (3) p = 0.436 | 0.60 ± 0.14 (5) p = 0.157 | 0.50 ± 0.06 (4) p = 0.110 | 0.26 (1)

ATP = adenosine 5’-triphosphate.

^a^ Livers from terminal sacrifice and moribund animals were evaluated. Livers from dead animals were not evaluated. Values are expressed as mean ± standard error with sample number in parentheses.

^b^ Target dose in mg/kg/day.

^c^ Actual dose calculated from observed body weight and feed consumption data.

^d^ Number of samples examined shown in parentheses. Liver samples from some of the rats were not available for assay due to problems with freezer storage.

^e^ Significance given with the control group is the dose trend; that given with other dose groups is the difference from the control group on a one-tailed Dunnett test.

Table J-6 Hepatic Adenosine 5’-Triphosphate Concentrations in Mice Exposed to (+)-Usnic Acid for Two Weeks^a^

| 0 ppm | 30 ppm (5)^b^ | 60 ppm (10) | 180 ppm (30) | 600 ppm (100) | 1,200 ppm (200)
Male
Observed Dose^c^ | 0 | 8.4 | 15.4 | 44.1 | 145 | 336
ATP (µmol/g) | 1.64 ± 0.21 (4)^d^ p ≤ 0.001^e^ | 1.75 ± 0.19 (5) p = 0.910 | 1.32 ± 0.16 (5) p = 0.332 | 0.85 ± 0.22 (5) p = 0.016 | 0.96 ± 0.17 (5) p = 0.039 | 0.71 ± 0.16 (5) p = 0.005
Female
Observed Dose | 0 | 9.4 | 19.6 | 50.1 | 195 | 326
ATP (µmol/g) | 1.21 ± 0.17 (5) p = 0.020 | 0.86 ± 0.13 (5) p = 0.167 | 1.05 ± 0.08 (5) p = 0.519 | 0.79 ± 0.18 (5) p = 0.091 | 0.64 ± 0.16 (5) p = 0.021 | 0.64 ± 0.11 (4) p = 0.027

ATP = adenosine 5’-triphosphate.

^a^ Livers from terminal sacrifice and moribund animals were evaluated. Livers from dead animals were not evaluated. Values are expressed as mean ± standard error with sample number in parentheses.

^b^ Target dose in mg/kg/day.

^c^ Actual dose calculated from observed body weight and feed consumption data.

^d^ Number of samples examined shown in parentheses.

^e^ Significance given with the control group is the dose trend; that given with other dose groups is the difference from the control group on a one-tailed Dunnett test.

Table J-7 Serum Triglyceride and Cholesterol Concentrations in Rats Exposed to (+)-Usnic Acid for Two Weeks^a^

| 0 ppm | 60 ppm (5) | 120 ppm (10) | 360 ppm (30) | 1,200 ppm (100) | 2,500 ppm (200)
Male
Triglyceride^b^ | 96.2 ± 9.8 (5) p = 0.0015^c^ | 126 ± 23 (5) p = 0.99 | 95.2 ± 12.2 (5) p = 0.83 | 126 ± 23 (5) p = 0.99 | 51.2 ± 7.1 (5) p = 0.102 | 41.0 ± 2.7 (3) p = 0.081
Cholesterol^d^ | 81.8 ± 5.9 (5) p = 0.78 | 85.2 ± 5.5 (5) p = 0.93 | 82.8 ± 3.4 (5) p = 0.87 | 114 ± 10 (5) p = 1.0 | 102 ± 6.7 (5) p = 0.99 | 86.3 ± 1.2 (3) p = 0.94
Female
Triglyceride | 81.4 ± 11.1 (5) p = 0.0006 | 71.2 ± 8.3 (5) p = 0.43 | 66.2 ± 4.4 (5) p = 0.23 | 64.0 ± 4.9 (5) p = 0.17 | 54.0 ± 6.9 (5) p = 0.027 | 34.3 ± 3.4 (3) p = 0.001
Cholesterol | 106 ± 5.7 (5) p ≤ 0.0001 | 102 ± 1.9 (5) p = 0.66 | 115 ± 5.9 (5) p = 1.0 | 123 ± 3.7 (5) p = 1.0 | 90.4 ± 2.4 (5) p = 0.051 | 68.3 ± 8.6 (3) p = 0.0001

^a^ Values are expressed as mean ± standard error with sample number in parentheses.

^b^ Activity given as units/L.

^c^ p values listed under the control group values denote trend test significance, and those beneath the dosed group values denote significance of Dunnett test pairwise comparisons between the feed controls and that dosed group. Two-tailed Dunnett tests were used.

^d^ Concentrations given as mg/dL.

Figure J-1

Effect of Two-week Exposure to (+)-Usnic Acid in Feed on Mean Body Weight in Rats

Figure J-2

Effect of Two-week Exposure to (+)-Usnic Acid in Feed on Mean Body Weight in Mice

Figure J-3

Survival of Rats Exposed to (+)-Usnic Acid in Feed for Two Weeks

Figure J-4

Survival of Mice Exposed to (+)-Usnic Acid in Feed for Two Weeks

Figure J-5

Serum Leptin Concentrations in Female Rats Exposed to (+)-Usnic Acid for Two Weeks

HALO denotes hours after lights on.

Figure J-6

Hepatic Tyrosine Aminotransferase in Cytosol from Male Rats Exposed to (+)-Usnic Acid for Two Weeks

Asterisks denote significant pairwise comparison to control group (Dunnett test); statistically significant at p ≤ 0.05 (*).