# Appendix I Ingredients, Nutrient Composition, and Contaminant Levels in NIH-41 Rodent Diet

Table I-1 Ingredients of NIH-41 Irradiated Diet

Ingredients | Percentage by Weight
Ground Whole Hard Wheat | 34.9
Ground #2 Yellow Corn | 21.0
Ground Whole oats | 10.0
Wheat Middlings | 10.0
Fish Meal (60% Protein) | 9.0
Soy Oil | 2.0
Soybean Meal (47.5% Protein) | 5.0
Alfalfa Meal (17% Protein) | 2.0
Corn Gluten Meal (60% Protein) | 2.0
Dicalcium Phosphate | 1.5
Brewers Dried Yeast | 1.0
Premixes | 0.5
Ground Limestone | 0.5
Salt | 0.5

Table I-2 Vitamins and Minerals in NIH-41 Irradiated Diet

| Amount | Source
Vitamins
A | 14,500,000 IU | Vitamin A palmitate or acetate
D_3_ | 4,6000,000 IU | D-activated animal sterol
K | 2.8 g | Menadione activity
dl-Alpha-tocopheryl Acetate | 20,000 IU
Choline | 560 g | Choline chloride
Folic Acid | 2.2 g
Niacin | 30.0 g
d-Pantothenic Acid | 18.0 g | d-Calcium pantothenate
Riboflavin Supplement | 6.6 g
Thiamin | 10 g | Thiamin mononitrate
B_12_ | 58.2 mg
Pyridoxine | 1.7 g | Pyridoxine hydrochloride
Biotin | 113.5 mg | d-Biotin
Minerals
Cobalt | 400 mg | Cobalt carbonate
Copper | 4 g | Copper sulfate
Iron | 60 g | Iron sulfate
Magnesium | 400 g | Magnesium oxide
Manganese | 100 g | Manganese oxide
Zinc | 10 g | Zinc oxide
Iodine | 1,500 mg | Calcium iodate

Table I-3 Results of Analyses for Nutrients and Contaminants in NIH-41 Irradiated Diet^a^

Diet Sample SCR # | 1456100001 | 1456100006 | Average
Diet Lot # | 042908M | 072908M
Nutrients
Protein (% by wt.) | 17.7 | 17.3 | 17.5
Total Fat (% by wt.) | 7.90 | 9.45 | 8.68
Vitamin A, ppm | 3.33 | 3.48 | 3.41
Vitamin B_1_, ppm | 27.6 | 16.1 | 21.9
Vitamin E, ppm | 28.4 | 37.0 | 32.7
Contaminants
Acrylamide, ppm | <LOQ | <LOQ | <LOQ
Aflatoxin-G_1_, ppb | <MDL^c^ | <MDL | <MDL
Aflatoxin-B_1_, ppb | <MDL | <MDL | <MDL
Aflatoxin-B_2_, ppb | <MDL | <MDL | <MDL
Aflatoxin-G_2_, ppb | <MDL | <MDL | <MDL
Total Fumonisins, ppb | 166 | 120 | 143
Volatiles (% by wt.) | 8.35 | 9.45 | 8.68
Pb, ppm | 0.28 | 0 | 0.14
Se, ppm | 0.38 | 0.40 | 0.39
As, ppm | 0.20 | 0.19 | 0.20
Cd, ppm | 0 | 0.12 | 0.06

LOQ = limit of quantification (20 ppm); MDL = method detection limit (0.1 ppb for aflatoxins).

^a^ Analyzed in lots that were used for the study.