# Appendix H Chemical Characteristics and Dose Formulation Studies

## H.1 Procurement and Characterization of Usnic Acid

(+)-Usnic acid [(d)-usnic acid, 2,6-diacetyl-7,9-dihydroxy-8,9b(R)-dimethyldibenzofuran-1,3(2H,9bH)-dione] was obtained from Sigma-Aldrich Co. (Milwaukee, WI) in one lot (02503HD). Identity, purity, and stability analyses were conducted by the study laboratory. Reports on the analyses performed in support of the study of usnic acid are on file at the National Center for Toxicological Research (NCTR).

The chemical, a bright-yellow powder, was identified as (+)-usnic acid by the study laboratory using ^1^H and ^13^C nuclear magnetic resonance (NMR), high-performance liquid chromatography (HPLC), gas chromatography, and HPLC-photodiode array (PDA) with electrospray ionization mass spectrometry (HPLC-/+ESI-MS, GC/EI-MS, and HPLC-PDA-\+ESI-MS) and MS/MS. All spectra were consistent with the structure of usnic acid and the GC/MS results showed one component which matched the NIST 2005 library for (+)-usnic acid (Figure H-1, Figure H-2, and Figure H-3).

The purity of lot 02503HD was determined by the study laboratory using HPLC-PDA (Waters, Milford, MA), with a mobile phase of 73% acetonitrile:27% water, 0.05% formic acid at a flow rate of 1.1 mL/minute through a Phenomenex Prodigy ODS-3 (250 mm × 4.6 mm, 5 μm, 100 Å pore size) C18 HPLC column for 30 minutes. Consistent with the extracted wavelengths from 200 to 600 nm, a Max-plot chromatogram was compared to the solvent blank and the estimated purity was determined to be 99.7%. Purity was verified using ^1^H and ^13^C NMR, which indicated a 2.6% impurity on a molar basis. The overall purity of lot 02503HD was determined to be approximately 98%.

(+)-Usnic acid was stable at normal temperature and pressures.

## H.2 Preparation and Analyses of Dose Formulations

The dose formulations were prepared approximately every 6–8 weeks by hand blending a premix and blending with additional feed in a Patterson-Kelly twin-shell blender (Table H-1). Dose formulations were stored in stainless-steel feed cans at 2°C–8°C for up to 55 days.

Homogeneity and stability studies were performed on the 15 ppm dose formulations by the study laboratory using the HPLC-PDA method described above. Homogeneity and stability were confirmed for 14 days at room temperature and up to 17 weeks at 2°C–8°C.

Analyses of the dose formulations were conducted using the HPLC-PDA method described above. All dose formulations were analyzed (Table H-2). All dose formulations were within 10% of the target concentration.

Table H-1 Preparation and Storage of Dose Formulations in the Three-month Feed Studies of (+)-Usnic Acid

Preparation
A premix of usnic acid and feed was ground by hand with a mortar and pestle, then combined with the remaining feed and blended in a Patterson-Kelly twin-shell blender with the intensifier bar on for 30 minutes. Two batches of the 15 ppm dose formulation and three batches each of the 30, 60, 120, 180, 360, and 720 ppm dose formulations were prepared. The dose formulations were prepared approximately every 6–8 weeks. Cage feeders were changed weekly.
Chemical Lot Number
02503HD
Storage Conditions
Stored in stainless-steel feed cans at 2°C–8°C
Study Laboratory
National Center for Toxicological Research (Jefferson, AR)

Table H-2 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Feed Studies of (+)-Usnic Acid

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
Rats and Mice
July 29, 2008 | July 29, 2008 | 15^b^ | 14.3 ± 1.0 | –4.4
| | 30 | 28.6 ± 0.6 | –4.8
| | 60 | 55.1 ± 0.3 | –8.1
| | 120 | 111 ± 0 | –7.7
| | 180 | 168 ± 1 | –6.6
| | 360 | 344 ± 1 | –4.6
| | 720 | 688 ± 1 | –4.5
September 9, 2008 | September 9, 2008 | 30 | 27.3 ± 0.5 | –9.1
| | 60 | 56.0 ± 0.6 | –6.7
| | 120 | 118 ± 0 | –1.5
| | 360 | 339 ± 8 | –5.8
| | 720 | 674 ± 9 | –6.4
September 30, 2008 | September 30, 2008 | 15^c^ | 15.0 ± 0.5 | –0.3
| | 180 | 181 ± 2 | 1
October 9, 2008 | October 9, 2008 | 30 | 30.4 ± 1.1 | 1
| | 60 | 57.4 ± 0.7 | –4.3
| | 120 | 115 ± 1 | –3.9
| | 360 | 357 ± 6 | –0.9
| | 720 | 699 ± 38 | –2.9

^a^ Results of three analyses (mean ± standard deviation). The limit of quantitation was estimated to be approximately 0.4 mg/kg diet.

^b^ n = 9.

^c^ n = 8.

Figure H-1

Chromatogram of (+)-Usnic Acid

Figure H-2

Mass Spectrum of (+)-Usnic Acid

Figure H-3

Ultraviolet Spectrum of (+)-Usnic Acid