# Appendix G Reproductive Toxicology Studies

Table G-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm^a,b^ | 120 ppm | 360 ppm | 720 ppm
Weights (g)^c^
Necropsy body weight | 345.5 ± 5.27 | 338.7 ± 4.00 | 336.2 ± 5.73 | 320.3 ± 3.45**
L. cauda epididymis | 0.222 ± 0.0062 | 0.206 ± 0.0080 | 0.225 ± 0.0062 | 0.241 ± 0.0157
L. epididymis | 0.477 ± 0.0104 | 0.461 ± 0.0112 | 0.492 ± 0.0105 | 0.515 ± 0.0162
L. testis | 1.574 ± 0.0164 | 1.578 ± 0.0173 | 1.603 ± 0.0268 | 1.652 ± 0.0152**
Spermatid Measurements^d^
Spermatid heads (10^6^/g testis) | 134.24 ± 6.557 | 149.97 ± 9.901 | 148.08 ± 11.715 | 133.19 ± 14.652
Spermatid heads (10^6^/testis) | 211.29 ± 10.499 | 236.24 ± 15.363 | 238.03 ± 20.099 | 219.19 ± 23.884
Epididymal Spermatozoal Measurements^d^
% Sperm motility | 87.1 ± 1.24 | 86.7 ± 1.15 | 87.2 ± 0.81 | 85.5 ± 1.22
Sperm (10^6^/g cauda epididymis) | 839.8 ± 15.79 | 854.5 ± 15.46 | 833.4 ± 14.81 | 783.0 ± 42.92
Sperm (10^6^/cauda epididymis) | 186.1 ± 5.93 | 176.4 ± 7.94 | 187.1 ± 5.58 | 183.7 ± 5.00

^a^ n = 10 for each group.

^b^ Data are presented as mean ± standard error.

^c^ Each dose is compared to the control with the William’s test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunnett’s test is applied (** = p ≤ 0.01).

^d^ Each dose is compared to the control with Shirley’s test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunn’s test is applied.

Table G-2 Estrous Cycle Characterization for Female Rats in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm^a,b^ | 120 ppm | 360 ppm | 720 ppm
Necropsy Body Weight (g)^c^ | 198.2 ± 4.52 | 195.8 ± 3.95 | 184.8 ± 3.22 | 168.6 ± 2.24
Proportion of Regular Cycling Females^d^ | 10/10 | 10/10 | 10/10 | 7/10
Estrous Cycle Length (days)^e^ | 5.0 ± 0.00 | 5.0 ± 0.00 | 5.0 ± 0.00 | 5.2 ± 0.15*
Estrous Stages (% of cycle)^f^
Diestrus | 57.5 | 59.4 | 56.3 | 69.4**
Proestrus | 19.4 | 20.6 | 20.6 | 13.1
Estrus | 19.4 | 20.0 | 21.3 | 13.8
Metestrus | 1.9 | 0.0 | 0.6 | 0.0
Uncertain diagnosis | 1.9 | 0.0 | 1.3 | 3.8

^a^ n = 10 for each group.

^b^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error.

^c^ Statistically evaluated using the William’s and Dunnett’s tests

^d^ Number of females with a regular cycle/number of females cycling.

^e^ Statistically evaluated using the Shirley’s and Dunn’s tests (* p ≤ 0.05).

^f^ By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated a significantly extended diestrus in the 720 ppm group relative to the control group ** p ≤ 0.01). No other significant differences in transition probabilities among the groups were observed.

Table G-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm^a,b^ | 60 ppm | 180 ppm | 360 ppm
Weights (g)^c^
Necropsy body weight | 28.3 ± 0.62 | 28.0 ± 0.68 | 27.2 ± 0.65 | 26.4 ± 0.40
L. cauda epididymis | 0.020 ± 0.0009 | 0.018 ± 0.0009 | 0.017 ± 0.0009 | 0.017 ± 0.0010
L. epididymis | 0.050 ± 0.0015 | 0.048 ± 0.0021 | 0.047 ± 0.0017 | 0.045 ± 0.0013
L. testis | 0.118 ± 0.0024 | 0.115 ± 0.0027 | 0.116 ± 0.0030 | 0.113 ± 0.0022
Spermatid Measurements^d^
Spermatid heads (10^6^/g testis) | 222.01 ± 28.547 | 263.46 ± 15.699 | 222.59 ± 19.137 | 222.38 ± 14.054
Spermatid heads (10^6^/testis) | 26.51 ± 3.677 | 30.22 ± 2.008 | 25.62 ± 2.123 | 25.17 ± 1.587
Epididymal Spermatozoal Measurements^d^
% Sperm motility | 85.3 ± 1.15 | 84.4 ± 0.78 | 86.5 ± 1.11 | 84.6 ± 1.42
Sperm (10^6^/g cauda epididymis) | 856.9 ± 14.86 | 810.6 ± 30.55 | 840.3 ± 22.16 | 818.5 ± 13.17
Sperm (10^6^/cauda epididymis) | 17.2 ± 0.98 | 14.8 ± 1.06 | 14.5 ± 0.96 | 14.1 ± 0.87

^a^ n = 10 for each group.

^b^ Data are presented as mean ± standard error.

^c^ Each dose is compared to the control with the Williams test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunnett’s test is applied.

^d^ Each dose is compared to the control with the Shirley test when a trend is present, p ≤ 0.01 from Jonckheere’s trend test, otherwise Dunn’s test is applied.

Table G-4 Estrous Cycle Characterization for Female Mice in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm^a,b^ | 60 ppm | 180 ppm | 360 ppm
Necropsy Body Weight (g)^c^ | 21.9 ± 0.31 | 21.6 ± 0.59 | 22.0 ± 0.39 | 22.2 ± 0.45
Proportion of Regular Cycling Females^d^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous Cycle Length (days)^e^ | 4.7 ± 0.60 | 4.3 ± 0.26 | 5.7 ± 0.94 | 4.4 ± 0.30
Estrous Stages (% of cycle)^f^
Diestrus | 48.8 | 53.1 | 49.4 | 46.9
Proestrus | 3.8 | 3.1 | 5.6 | 2.5
Estrus | 31.3 | 31.9 | 26.3 | 40.0
Metestrus | 11.3 | 9.4 | 11.9 | 8.1
Uncertain diagnosis | 5.0 | 2.5 | 6.9 | 2.5

^a^ n = 10 for each group.

^b^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error.

^c^ Statistically evaluated using the William’s and Dunnett’s tests.

^d^ Number of females with a regular cycle/number of females cycling.

^e^ Statistically evaluated using Shirley’s and Dunn’s tests.

^f^ By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices were conducted among all groups and between the vehicle control group and each dosed group. No significant differences in transition probabilities among the groups were observed.