# Appendix F Feed Consumption, Target Dose, and Water Consumption

Table F-1 Feed Consumption of Male Rats in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 21.2 ± 0.8 | 0.737 | 10 | 20.6 ± 0.8 | 0.934 | 10 | 19.0 ± 0.6 | 0.096 | 10 | 20.9 ± 0.6 | 0.997 | 10 | 19.9 ± 0.7 | 0.521 | 10 | 20.9 ± 0.7 | 0.997
2 | 10 | 21.6 ± 0.5 | 0.027 | 10 | 21.1 ± 0.8 | 0.992 | 10 | 19.6 ± 0.8 | 0.246 | 10 | 21.3 ± 1.0 | 0.998 | 10 | 21.4 ± 0.6 | 1.000 | 10 | 23.0 ± 1.0 | 0.616
3 | 10 | 21.5 ± 0.9 | 0.298 | 10 | 21.1 ± 0.4 | 0.999 | 10 | 20.4 ± 1.0 | 0.820 | 10 | 21.8 ± 0.9 | 0.998 | 10 | 22.1 ± 0.9 | 0.966 | 10 | 21.9 ± 0.6 | 0.994
4 | 10 | 22.4 ± 1.0 | 0.334 | 10 | 21.4 ± 1.1 | 0.871 | 10 | 20.2 ± 0.6 | 0.199 | 10 | 21.4 ± 0.6 | 0.861 | 10 | 20.7 ± 0.7 | 0.448 | 10 | 22.6 ± 0.8 | 1.000
5 | 10 | 23.4 ± 0.7 | 0.265 | 10 | 23.7 ± 0.9 | 0.997 | 10 | 22.8 ± 0.8 | 0.977 | 10 | 21.6 ± 0.6 | 0.323 | 10 | 23.2 ± 0.9 | 1.000 | 10 | 24.1 ± 0.6 | 0.944
6 | 10 | 22.8 ± 1.1 | 0.250 | 10 | 22.9 ± 0.6 | 1.000 | 10 | 21.2 ± 0.7 | 0.433 | 10 | 21.9 ± 0.9 | 0.867 | 10 | 22.5 ± 0.7 | 0.999 | 10 | 23.3 ± 0.6 | 0.986
7 | 10 | 23.8 ± 1.0 | 0.647 | 10 | 22.5 ± 1.1 | 0.766 | 10 | 22.5 ± 0.6 | 0.800 | 10 | 23.2 ± 0.8 | 0.992 | 10 | 23.3 ± 1.0 | 0.995 | 10 | 23.5 ± 1.0 | 1.000
8 | 10 | 23.8 ± 0.9 | 0.749 | 10 | 23.3 ± 1.3 | 0.996 | 10 | 21.4 ± 0.9 | 0.265 | 10 | 22.7 ± 0.8 | 0.875 | 10 | 23.4 ± 1.3 | 0.999 | 10 | 23.2 ± 0.7 | 0.987
9 | 10 | 22.9 ± 1.1 | 0.603 | 10 | 22.7 ± 0.9 | 1.000 | 10 | 23.2 ± 0.9 | 1.000 | 10 | 22.1 ± 1.2 | 0.985 | 10 | 24.5 ± 1.1 | 0.723 | 10 | 23.0 ± 1.2 | 1.000
10 | 10 | 22.3 ± 0.9 | 0.572 | 10 | 22.8 ± 0.7 | 0.993 | 10 | 20.6 ± 0.9 | 0.538 | 10 | 23.9 ± 1.3 | 0.604 | 10 | 22.8 ± 0.8 | 0.996 | 10 | 22.8 ± 0.7 | 0.996
11 | 10 | 22.0 ± 1.1 | 0.040 | 10 | 23.2 ± 0.7 | 0.810 | 10 | 21.1 ± 0.9 | 0.910 | 10 | 22.1 ± 1.1 | 1.000 | 10 | 22.8 ± 0.5 | 0.970 | 10 | 24.2 ± 0.7 | 0.277
12 | 10 | 23.1 ± 1.7 | 0.564 | 10 | 24.1 ± 1.0 | 0.985 | 10 | 23.0 ± 1.8 | 1.000 | 10 | 24.0 ± 1.2 | 0.993 | 10 | 23.4 ± 1.2 | 1.000 | 10 | 24.6 ± 1.5 | 0.932
13 | 10 | 24.2 ± 1.1 | 0.001 | 10 | 22.7 ± 0.9 | 0.846 | 10 | 23.4 ± 0.8 | 0.985 | 10 | 23.7 ± 1.2 | 0.999 | 10 | 25.6 ± 1.5 | 0.864 | 10 | 27.7 ± 1.4 | 0.128
Mean for Weeks
1–13 | | 22.7 ± 0.3 | 0.001 | | 22.5 ± 0.3 | 0.977 | | 21.4 ± 0.3 | 0.011 | | 22.3 ± 0.3 | 0.856 | | 22.7 ± 0.3 | 1.000 | | 23.5 ± 0.3 | 0.237

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the dosed columns are Dunnett's adjusted p values for pairwise comparisons of the dosed groups to the 0 ppm group.

Table F-2 Feed Consumption of Female Rats in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 16.6 ± 1.5 | 0.101 | 10 | 15.7 ± 0.7 | 0.971 | 10 | 15.0 ± 0.7 | 0.752 | 10 | 17.3 ± 1.5 | 0.988 | 10 | 14.8 ± 0.7 | 0.637 | 10 | 14.3 ± 0.7 | 0.402
2 | 10 | 15.4 ± 0.8 | 0.977 | 10 | 18.2 ± 1.0 | 0.050 | 10 | 15.6 ± 0.7 | 1.000 | 10 | 16.3 ± 0.9 | 0.905 | 10 | 15.4 ± 0.6 | 1.000 | 10 | 16.7 ± 0.3 | 0.684
3 | 10 | 17.5 ± 0.8 | 0.327 | 10 | 18.2 ± 0.6 | 0.971 | 10 | 18.7 ± 1.0 | 0.773 | 10 | 16.6 ± 1.1 | 0.935 | 10 | 17.6 ± 1.2 | 1.000 | 10 | 16.8 ± 0.5 | 0.981
4 | 10 | 18.5 ± 1.3 | 0.945 | 10 | 18.6 ± 0.9 | 1.000 | 10 | 17.9 ± 0.6 | 0.980 | 10 | 17.9 ± 0.7 | 0.981 | 10 | 18.2 ± 0.9 | 0.999 | 10 | 18.4 ± 0.6 | 1.000
5 | 10 | 17.6 ± 1.0 | 0.710 | 10 | 18.2 ± 0.9 | 0.987 | 10 | 17.1 ± 0.6 | 0.991 | 10 | 18.9 ± 1.1 | 0.759 | 10 | 19.0 ± 0.7 | 0.717 | 10 | 17.9 ± 0.9 | 0.999
6 | 10 | 18.1 ± 0.8 | 0.284 | 10 | 19.1 ± 1.1 | 0.887 | 10 | 19.5 ± 0.9 | 0.666 | 10 | 17.7 ± 1.0 | 0.996 | 10 | 17.8 ± 0.8 | 1.000 | 10 | 17.7 ± 0.7 | 0.999
7 | 10 | 19.8 ± 0.8 | 0.649 | 10 | 17.9 ± 1.1 | 0.567 | 10 | 18.7 ± 1.1 | 0.912 | 10 | 18.6 ± 0.7 | 0.903 | 10 | 19.2 ± 1.1 | 0.996 | 10 | 19.3 ± 1.3 | 0.997
8 | 10 | 17.8 ± 1.1 | 0.633 | 10 | 17.2 ± 0.8 | 0.992 | 10 | 18.2 ± 0.9 | 0.997 | 10 | 16.4 ± 0.9 | 0.754 | 10 | 18.4 ± 0.8 | 0.986 | 10 | 17.8 ± 0.7 | 1.000
9 | 10 | 17.6 ± 0.8 | 0.683 | 10 | 19.0 ± 1.3 | 0.782 | 10 | 18.0 ± 0.9 | 0.999 | 10 | 18.2 ± 0.9 | 0.992 | 10 | 19.4 ± 1.0 | 0.563 | 10 | 18.3 ± 0.9 | 0.983
10 | 10 | 17.1 ± 0.4 | 0.766 | 10 | 18.1 ± 0.6 | 0.880 | 10 | 17.5 ± 0.8 | 0.997 | 10 | 20.0 ± 1.5 | 0.087 | 10 | 16.9 ± 1.0 | 1.000 | 10 | 18.5 ± 0.7 | 0.683
11 | 10 | 20.4 ± 1.3 | 0.935 | 10 | 17.9 ± 0.9 | 0.231 | 10 | 16.4 ± 1.0 | 0.012 | 10 | 17.2 ± 0.9 | 0.064 | 10 | 17.9 ± 0.8 | 0.225 | 10 | 18.3 ± 0.8 | 0.362
12 | 10 | 16.9 ± 1.0 | 0.057 | 10 | 19.1 ± 1.0 | 0.481 | 10 | 16.2 ± 0.7 | 0.989 | 10 | 19.4 ± 1.3 | 0.372 | 10 | 18.7 ± 1.2 | 0.696 | 10 | 20.1 ± 1.2 | 0.163
13 | 10 | 18.7 ± 1.2 | 0.695 | 10 | 20.5 ± 1.1 | 0.623 | 10 | 18.0 ± 0.7 | 0.990 | 10 | 18.7 ± 1.1 | 1.000 | 10 | 19.2 ± 1.2 | 0.998 | 10 | 19.5 ± 1.2 | 0.974
Mean for Weeks
1–13 | | 17.8 ± 0.3 | 0.821 | | 18.3 ± 0.3 | 0.738 | | 17.4 ± 0.3 | 0.810 | | 17.9 ± 0.3 | 1.000 | | 17.9 ± 0.3 | 1.000 | | 18.0 ± 0.3 | 0.998

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the dosed columns are Dunnett's adjusted p values for pairwise comparisons of the dosed groups to the 0 ppm group.

Table F-3 Feed Consumption of Male Mice in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | | Mean ± SE | P Value
1 | 10 | 6.6 ± 0.6 | 0.292 | 10 | 7.7 ± 1.0 | 0.723 | 10 | 8.4 ± 1.1 | 0.340 | 10 | 6.1 ± 0.3 | 0.992 | 10 | 6.2 ± 0.6 | 0.998 | 10 | | 6.5 ± 0.7 | 1.000
2 | 10 | 8.3 ± 0.8 | 0.493 | 10 | 6.5 ± 0.7 | 0.417 | 10 | 8.4 ± 0.8 | 1.000 | 10 | 6.2 ± 0.6 | 0.264 | 10 | 7.1 ± 0.8 | 0.761 | 10 | | 8.3 ± 1.0 | 1.000
3 | 10 | 6.5 ± 0.5 | 0.234 | 10 | 7.4 ± 0.7 | 0.764 | 10 | 7.3 ± 0.6 | 0.863 | 10 | 7.3 ± 0.7 | 0.806 | 10 | 6.7 ± 0.6 | 1.000 | 10 | | 6.3 ± 0.4 | 0.999
4 | 10 | 6.6 ± 0.7 | 0.065 | 10 | 8.3 ± 1.3 | 0.573 | 10 | 9.9 ± 1.2 | 0.054 | 10 | 6.5 ± 0.8 | 1.000 | 10 | 6.9 ± 0.8 | 1.000 | 10 | | 5.9 ± 0.6 | 0.989
5 | 10 | 7.4 ± 0.6 | 0.956 | 10 | 7.3 ± 0.7 | 1.000 | 10 | 6.3 ± 0.8 | 0.835 | 10 | 6.3 ± 0.7 | 0.831 | 10 | 7.0 ± 1.1 | 0.996 | 10 | | 6.9 ± 1.1 | 0.990
6 | 10 | 7.0 ± 0.7 | 0.027 | 10 | 7.8 ± 0.9 | 0.888 | 10 | 8.2 ± 0.7 | 0.701 | 10 | 8.8 ± 1.0 | 0.310 | 10 | 6.7 ± 0.4 | 0.997 | 10 | | 6.1 ± 0.3 | 0.843
7 | 10 | 6.6 ± 0.5 | 0.628 | 10 | 8.9 ± 1.0 | 0.170 | 10 | 7.0 ± 0.6 | 0.995 | 10 | 7.4 ± 0.8 | 0.938 | 10 | 7.3 ± 0.7 | 0.958 | 10 | | 7.0 ± 1.0 | 0.995
8 | 10 | 8.0 ± 0.7 | 0.901 | 10 | 7.7 ± 1.2 | 0.999 | 10 | 6.5 ± 0.5 | 0.543 | 10 | 7.0 ± 0.8 | 0.852 | 10 | 7.0 ± 0.9 | 0.885 | 10 | | 7.4 ± 0.5 | 0.977
9 | 10 | 7.6 ± 0.5 | 0.599 | 10 | 7.2 ± 1.0 | 0.997 | 10 | 7.1 ± 0.8 | 0.992 | 10 | 8.0 ± 1.0 | 0.998 | 10 | 6.5 ± 0.8 | 0.809 | 10 | | 7.2 ± 0.6 | 0.995
10 | 10 | 7.2 ± 0.8 | 0.231 | 10 | 7.1 ± 1.0 | 1.000 | 10 | 6.7 ± 1.0 | 0.994 | 10 | 7.2 ± 0.8 | 1.000 | 10 | 6.8 ± 1.0 | 0.997 | 10 | | 8.5 ± 1.0 | 0.785
11 | 10 | 7.3 ± 0.8 | 0.899 | 10 | 6.9 ± 0.5 | 0.998 | 10 | 8.0 ± 0.9 | 0.982 | 10 | 7.4 ± 1.4 | 1.000 | 10 | 6.9 ± 0.8 | 0.998 | 10 | | 7.7 ± 1.2 | 0.999
12 | 10 | 6.4 ± 0.6 | 0.040 | 10 | 6.5 ± 0.3 | 1.000 | 10 | 6.3 ± 0.5 | 1.000 | 10 | 7.4 ± 0.9 | 0.784 | 10 | 7.1 ± 0.9 | 0.932 | 10 | | 8.3 ± 1.0 | 0.242
13 | 10 | 8.2 ± 1.1 | 0.807 | 10 | 7.3 ± 0.7 | 0.946 | 10 | 7.8 ± 0.9 | 0.998 | 10 | 8.2 ± 1.1 | 1.000 | 10 | 8.7 ± 1.0 | 0.997 | 10 | | 7.3 ± 0.9 | 0.948
Mean for Weeks
1–13 | | 7.2 ± 0.2 | 0.376 | | 7.4 ± 0.2 | 0.935 | | 7.5 ± 0.2 | 0.806 | | 7.2 ± 0.2 | 1.000 | | 7.0 ± 0.2 | 0.951 | | | 7.2 ± 0.2 | 1.000

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the dosed columns are Dunnett's adjusted p values for pairwise comparisons of the dosed groups to the 0 ppm group.

Table F-4 Feed Consumption of Female Mice in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 6.3 ± 0.7 | 0.292 | 10 | 7.5 ± 0.7 | 0.571 | 10 | 6.8 ± 0.6 | 0.986 | 10 | 7.9 ± 0.8 | 0.316 | 10 | 5.9 ± 0.7 | 0.989 | 10 | 6.5 ± 0.3 | 1.000
2 | 10 | 6.1 ± 0.4 | 0.425 | 10 | 6.5 ± 0.5 | 0.988 | 10 | 8.0 ± 0.9 | 0.098 | 10 | 7.2 ± 0.3 | 0.592 | 10 | 7.2 ± 0.7 | 0.630 | 10 | 7.4 ± 0.5 | 0.456
3 | 10 | 7.5 ± 0.9 | 0.932 | 10 | 7.7 ± 0.7 | 1.000 | 10 | 7.3 ± 0.4 | 1.000 | 10 | 7.9 ± 0.9 | 0.998 | 10 | 7.2 ± 0.5 | 0.999 | 10 | 7.8 ± 1.0 | 1.000
4 | 10 | 7.2 ± 0.6 | 0.258 | 10 | 6.8 ± 0.7 | 0.994 | 9 | 6.9 ± 0.7 | 0.997 | 10 | 6.5 ± 0.6 | 0.920 | 10 | 7.8 ± 1.0 | 0.973 | 10 | 7.7 ± 0.8 | 0.991
5 | 10 | 7.4 ± 1.1 | 0.399 | 10 | 8.1 ± 0.9 | 0.967 | 9 | 7.0 ± 0.8 | 0.998 | 10 | 7.4 ± 0.7 | 1.000 | 10 | 6.3 ± 0.4 | 0.823 | 10 | 7.0 ± 1.0 | 0.997
6 | 10 | 7.5 ± 0.9 | 0.144 | 10 | 8.8 ± 0.9 | 0.802 | 9 | 6.4 ± 1.0 | 0.869 | 10 | 9.0 ± 1.4 | 0.699 | 10 | 5.9 ± 0.6 | 0.636 | 10 | 6.7 ± 0.9 | 0.951
7 | 10 | 8.8 ± 0.7 | 0.080 | 10 | 10.6 ± 1.1 | 0.455 | 9 | 6.6 ± 0.7 | 0.259 | 10 | 7.7 ± 0.9 | 0.827 | 10 | 6.7 ± 0.9 | 0.274 | 10 | 7.3 ± 0.9 | 0.605
8 | 10 | 8.3 ± 1.0 | 0.418 | 10 | 9.4 ± 1.8 | 0.903 | 9 | 7.9 ± 0.7 | 1.000 | 10 | 7.3 ± 0.8 | 0.945 | 10 | 7.2 ± 0.7 | 0.922 | 10 | 7.6 ± 1.0 | 0.993
9 | 10 | 6.4 ± 0.8 | 0.533 | 10 | 8.1 ± 0.8 | 0.390 | 9 | 7.7 ± 0.9 | 0.680 | 10 | 7.2 ± 0.7 | 0.932 | 10 | 7.3 ± 0.7 | 0.899 | 10 | 7.9 ± 0.9 | 0.502
10 | 10 | 6.4 ± 0.5 | 0.055 | 10 | 7.9 ± 1.0 | 0.572 | 9 | 7.7 ± 1.2 | 0.668 | 10 | 5.8 ± 0.5 | 0.991 | 10 | 7.9 ± 0.8 | 0.529 | 10 | 8.7 ± 0.8 | 0.153
11 | 10 | 7.9 ± 1.3 | 0.853 | 10 | 6.9 ± 1.0 | 0.919 | 9 | 7.0 ± 0.9 | 0.962 | 10 | 6.8 ± 0.5 | 0.887 | 10 | 6.6 ± 0.7 | 0.840 | 10 | 7.6 ± 1.3 | 1.000
12 | 10 | 7.8 ± 0.6 | 0.180 | 10 | 7.3 ± 0.6 | 0.986 | 9 | 6.6 ± 0.5 | 0.699 | 10 | 8.0 ± 0.9 | 0.999 | 10 | 7.8 ± 0.6 | 1.000 | 10 | 8.5 ± 1.0 | 0.941
13 | 10 | 7.9 ± 1.0 | 0.233 | 10 | 7.9 ± 0.6 | 1.000 | 9 | 7.4 ± 0.7 | 0.995 | 10 | 8.2 ± 0.6 | 0.999 | 10 | 8.8 ± 1.3 | 0.938 | 10 | 8.9 ± 1.0 | 0.902
Mean for Weeks
1–13 | | 7.4 ± 0.2 | 0.883 | | 8.0 ± 0.2 | 0.249 | | 7.2 ± 0.2 | 0.983 | | 7.5 ± 0.2 | 0.998 | | 7.1 ± 0.2 | 0.936 | | 7.7 ± 0.2 | 0.837

^a^ Feed changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the dosed columns are Dunnett's adjusted p values for pairwise comparisons of the dosed groups to the 0 ppm group.

Table F-5 Target and Observed Doses in Rats in the Three-month Feed Study of (+)-Usnic Acid

Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Observed Dose (mg/kg/day)^d^
Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Females | Males
30 | 2.5 | 2.91 ± 0.07 | 2.26 ± 0.08
60 | 5 | 5.51 ± 0.14 | 4.45 ± 0.13
120 | 10 | 11.64 ± 0.28 | 9.09 ± 0.31
360 | 30 | 35.64 ± 0.56 | 27.78 ± 0.80
720 | 60 | 76.98 ± 0.96 | 59.93 ± 1.80

^a^ Feed concentrations are denoted by their (+)-usnic acid content as ppm added to feed.

^b^ Doses were selected based on data obtained from 14-day feed studies (Appendix J) and historical data for the animal colonies.

^c^ Target dose estimate was calculated from historical body weight and feed consumption data for the animal colonies.

^d^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving rats in each dosed group. Observed feed consumption values do not correct for spillage. Data presented as mean ± standard error for the 13 weekly values.

Table F-6 Target and Observed Doses in Mice in the Three-month Feed Study of (+)-Usnic Acid

Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Observed Dose (mg/kg/day)^d^
Feed Concentration (ppm)^a,b^ | Target Dose (mg/kg/day)^c^ | Females | Males
15 | 2.5 | 5.38 ± 0.20 | 4.04 ± 0.15
30 | 5 | 9.84 ± 0.28 | 8.25 ± 0.46
60 | 10 | 20.92 ± 0.80 | 15.58 ± 0.36
180 | 30 | 58.04 ± 1.59 | 46.82 ± 0.96
360 | 60 | 124.37 ± 2.04 | 98.88 ± 3.19

^a^ Feed concentrations are denoted by their (+)-usnic acid content as ppm added to feed.

^b^ Doses were selected based on data obtained from 14-day feed studies (Appendix J) and historical data for the animal colonies.

^c^ Target dose estimate was calculated from historical body weight and feed consumption data for the animal colonies.

^d^ Observed values calculated from the observed weekly mean feed consumption and observed weekly mean body weights for surviving mice in each dose group. Observed feed consumption values do not correct for spillage. Data presented as mean and standard error for the 13 weekly values.

Table F-7 Water Consumption of Male Rats in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 24.1 ± 0.7 | 0.332 | 10 | 23.5 ± 1.3 | 0.994 | 10 | 22.8 ± 1.0 | 0.870 | 10 | 23.3 ± 0.9 | 0.970 | 10 | 24.6 ± 1.1 | 0.998 | 10 | 24.5 ± 1.4 | 0.999
2 | 10 | 23.4 ± 1.1 | 0.016 | 10 | 23.8 ± 0.8 | 0.995 | 10 | 21.1 ± 0.7 | 0.146 | 10 | 22.2 ± 0.7 | 0.710 | 10 | 23.7 ± 0.4 | 0.999 | 10 | 24.8 ± 0.8 | 0.530
3 | 10 | 22.7 ± 1.0 | 0.000 | 10 | 22.4 ± 1.0 | 1.000 | 10 | 22.8 ± 0.9 | 1.000 | 10 | 22.6 ± 0.7 | 1.000 | 10 | 23.7 ± 0.7 | 0.861 | 10 | 26.8 ± 1.1 | 0.005
4 | 10 | 23.7 ± 0.8 | 0.000 | 10 | 23.3 ± 1.1 | 0.999 | 10 | 23.1 ± 2.3 | 0.997 | 10 | 22.2 ± 0.5 | 0.840 | 10 | 23.6 ± 0.9 | 1.000 | 10 | 32.2 ± 0.9 | 0.000
5 | 10 | 22.2 ± 0.8 | 0.000 | 10 | 21.6 ± 0.6 | 0.957 | 10 | 21.2 ± 0.8 | 0.722 | 10 | 21.3 ± 0.4 | 0.815 | 10 | 22.3 ± 0.3 | 1.000 | 10 | 27.9 ± 0.8 | 0.000
6 | 10 | 22.6 ± 0.5 | 0.000 | 10 | 21.4 ± 0.8 | 0.616 | 10 | 20.8 ± 0.4 | 0.247 | 10 | 21.9 ± 1.0 | 0.916 | 10 | 22.5 ± 0.6 | 1.000 | 10 | 27.2 ± 0.7 | 0.000
7 | 10 | 23.7 ± 1.0 | 0.000 | 10 | 21.4 ± 0.7 | 0.154 | 10 | 21.0 ± 0.6 | 0.063 | 10 | 22.2 ± 1.0 | 0.545 | 10 | 22.9 ± 0.6 | 0.930 | 10 | 25.8 ± 0.7 | 0.257
8 | 10 | 22.6 ± 0.5 | 0.000 | 10 | 22.5 ± 0.7 | 1.000 | 10 | 20.9 ± 0.6 | 0.276 | 10 | 23.2 ± 1.1 | 0.969 | 10 | 22.5 ± 0.5 | 1.000 | 10 | 25.7 ± 0.6 | 0.006
9 | 10 | 22.5 ± 1.0 | 0.000 | 10 | 21.4 ± 0.6 | 0.801 | 10 | 21.2 ± 0.5 | 0.650 | 10 | 23.2 ± 1.1 | 0.952 | 10 | 23.7 ± 0.5 | 0.696 | 10 | 25.2 ± 0.8 | 0.055
10 | 10 | 23.8 ± 1.1 | 0.000 | 10 | 22.2 ± 0.9 | 0.748 | 10 | 21.4 ± 1.9 | 0.360 | 10 | 21.2 ± 0.5 | 0.313 | 10 | 24.3 ± 0.8 | 0.998 | 10 | 26.6 ± 0.8 | 0.226
11 | 10 | 23.5 ± 1.5 | 0.000 | 10 | 22.4 ± 0.9 | 0.881 | 10 | 19.2 ± 0.6 | 0.005 | 10 | 21.7 ± 0.6 | 0.485 | 10 | 24.9 ± 0.9 | 0.736 | 10 | 27.7 ± 0.7 | 0.005
12 | 10 | 21.9 ± 1.1 | 0.000 | 10 | 22.1 ± 1.0 | 1.000 | 10 | 19.3 ± 1.0 | 0.181 | 10 | 21.1 ± 0.5 | 0.973 | 10 | 26.2 ± 1.1 | 0.004 | 10 | 25.9 ± 0.8 | 0.010
13 | 10 | 21.3 ± 0.8 | 0.000 | 10 | 20.7 ± 1.2 | 0.990 | 10 | 20.1 ± 0.9 | 0.876 | 10 | 21.0 ± 0.8 | 1.000 | 10 | 25.4 ± 1.0 | 0.013 | 10 | 25.5 ± 1.2 | 0.009
Mean for Weeks
1–13 | | 22.9 ± 0.3 | 0.000 | | 22.2 ± 0.3 | 0.407 | | 21.1 ± 0.3 | 0.001 | | 22.1 ± 0.3 | 0.256 | | 23.9 ± 0.3 | 0.161 | | 26.6 ± 0.3 | 0.000

^a^ Water changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the dosed columns are Dunnett's adjusted p values for pairwise comparisons of the dosed groups to the 0 ppm group.

Table F-8 Water Consumption of Female Rats in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | P Value^d^ | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value | N | Mean ± SE | P Value
1 | 10 | 19.3 ± 1.0 | 0.614 | 10 | 18.9 ± 0.7 | 0.999 | 10 | 21.1 ± 1.0 | 0.502 | 10 | 20.3 ± 0.8 | 0.919 | 10 | 20.5 ± 1.1 | 0.822 | 10 | 19.0 ± 0.8 | 0.999
2 | 10 | 20.0 ± 0.5 | 0.211 | 10 | 19.8 ± 0.6 | 1.000 | 10 | 18.9 ± 0.7 | 0.767 | 10 | 19.9 ± 1.3 | 1.000 | 10 | 19.7 ± 0.7 | 0.999 | 10 | 20.9 ± 0.9 | 0.909
3 | 10 | 21.0 ± 0.6 | 0.347 | 10 | 20.8 ± 1.1 | 1.000 | 10 | 19.9 ± 0.4 | 0.795 | 10 | 19.9 ± 1.1 | 0.788 | 10 | 19.8 ± 0.6 | 0.745 | 10 | 19.8 ± 0.6 | 0.729
4 | 10 | 19.6 ± 0.6 | 0.008 | 10 | 20.4 ± 1.1 | 0.926 | 10 | 19.2 ± 0.8 | 0.991 | 10 | 19.4 ± 0.6 | 1.000 | 10 | 20.7 ± 0.6 | 0.808 | 10 | 22.0 ± 0.7 | 0.128
5 | 10 | 18.6 ± 0.6 | 0.000 | 10 | 19.6 ± 1.2 | 0.788 | 10 | 18.3 ± 0.6 | 0.999 | 10 | 19.0 ± 0.7 | 0.991 | 10 | 20.0 ± 0.6 | 0.550 | 10 | 24.6 ± 0.6 | 0.000
6 | 10 | 20.1 ± 1.3 | 0.001 | 10 | 19.5 ± 1.2 | 0.980 | 10 | 18.3 ± 0.5 | 0.412 | 10 | 17.8 ± 0.3 | 0.179 | 10 | 19.7 ± 0.4 | 0.999 | 10 | 22.2 ± 0.6 | 0.218
7 | 10 | 19.3 ± 1.1 | 0.101 | 10 | 18.3 ± 0.9 | 0.931 | 10 | 19.7 ± 1.8 | 1.000 | 10 | 18.9 ± 0.7 | 0.999 | 10 | 20.5 ± 0.6 | 0.892 | 10 | 20.8 ± 0.8 | 0.798
8 | 10 | 18.8 ± 1.1 | 0.000 | 10 | 18.2 ± 0.7 | 0.975 | 10 | 18.5 ± 0.7 | 0.998 | 10 | 17.7 ± 0.8 | 0.750 | 10 | 19.5 ± 0.4 | 0.943 | 10 | 21.8 ± 0.6 | 0.019
9 | 10 | 18.7 ± 0.7 | 0.000 | 10 | 19.4 ± 0.9 | 0.982 | 10 | 19.3 ± 1.1 | 0.994 | 10 | 19.7 ± 0.9 | 0.947 | 10 | 22.3 ± 1.1 | 0.058 | 10 | 25.0 ± 1.4 | 0.000
10 | 10 | 19.5 ± 0.7 | 0.000 | 10 | 20.4 ± 1.0 | 0.951 | 10 | 19.1 ± 1.2 | 0.999 | 10 | 18.7 ± 0.8 | 0.969 | 10 | 21.7 ± 0.9 | 0.346 | 10 | 24.6 ± 1.0 | 0.001
11 | 10 | 23.0 ± 2.2 | 0.000 | 10 | 19.3 ± 0.8 | 0.104 | 10 | 19.1 ± 1.1 | 0.073 | 10 | 19.7 ± 0.7 | 0.181 | 10 | 24.3 ± 0.8 | 0.920 | 10 | 25.9 ± 0.9 | 0.301
12 | 10 | 19.5 ± 0.9 | 0.000 | 10 | 20.0 ± 1.2 | 0.995 | 10 | 18.1 ± 0.8 | 0.751 | 10 | 20.1 ± 1.0 | 0.991 | 10 | 22.9 ± 0.7 | 0.043 | 10 | 23.7 ± 0.8 | 0.006
13 | 10 | 19.0 ± 1.3 | 0.004 | 10 | 20.6 ± 1.7 | 0.804 | 10 | 17.6 ± 0.7 | 0.907 | 10 | 19.3 ± 0.9 | 1.000 | 10 | 21.1 ± 1.1 | 0.635 | 10 | 23.0 ± 1.3 | 0.081
Mean for Weeks
1–13 | | 19.7 ± 0.3 | 0.000 | | 19.6 ± 0.3 | 1.000 | | 19.0 ± 0.3 | 0.311 | | 19.3 ± 0.3 | 0.718 | | 21.0 ± 0.3 | 0.020 | | 22.6 ± 0.3 | 0.000

Note: Water consumption was not analyzed for mice because large amounts of spillage occurred when cage lids were lifted, resulting in inaccurate measurements.

^a^ Water changed weekly and measured by cage.

^b^ N = number of cages.

^c^ Mean ± SE (g per day) = estimated least squares mean and standard error.

^d^ p values in the 0 ppm column are the p values for the trend test; p values in the dosed columns are Dunnett's adjusted p values for pairwise comparisons of the dosed groups to the 0 ppm group.