# Appendix E Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table E-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy Body Weight^a^ | 345 ± 5 | 345 ± 5 | 330 ± 6 | 339 ± 4 | 336 ± 6 | 320 ± 3**
Heart^b^
Absolute | 1.05 ± 0.02 | 1.05 ± 0.02 | 1.01 ± 0.02 | 1.05 ± 0.02 | 1.03 ± 0.02 | 1.02 ± 0.02
Relative | 3.05 ± 0.06 | 3.04 ± 0.06 | 3.08 ± 0.06 | 3.10 ± 0.06 | 3.08 ± 0.06 | 3.19 ± 0.06
R. Kidney
Absolute | 1.16 ± 0.02* | 1.13 ± 0.02 | 1.09 ± 0.02 | 1.13 ± 0.02 | 1.07 ± 0.02* | 1.09 ± 0.02
Relative | 3.37 ± 0.05 | 3.29 ± 0.05 | 3.31 ± 0.05 | 3.34 ± 0.05 | 3.19 ± 0.05 | 3.41 ± 0.05
Liver
Absolute | 10.40 ± 0.27***^c^ | 10.14 ± 0.26 | 9.83 ± 0.26 | 10.35 ± 0.26 | 10.93 ± 0.26 | 11.94 ± 0.26**
Relative | 30.23 ± 0.65***^c^ | 29.42 ± 0.61 | 29.78 ± 0.61 | 30.57 ± 0.61 | 32.48 ± 0.61 | 37.28 ± 0.61***
Lung
Absolute | 1.28 ± 0.03 | 1.23 ± 0.03 | 1.22 ± 0.03 | 1.25 ± 0.03 | 1.21 ± 0.03 | 1.24 ± 0.03
Relative | 3.71 ± 0.09 | 3.57 ± 0.09 | 3.69 ± 0.09 | 3.68 ± 0.09 | 3.60 ± 0.09 | 3.88 ± 0.09
Thymus
Absolute | 0.22 ± 0.01*^c^ | 0.21 ± 0.01 | 0.22 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01
Relative | 0.63 ± 0.03^c^ | 0.62 ± 0.03 | 0.65 ± 0.03 | 0.57 ± 0.03 | 0.56 ± 0.03 | 0.60 ± 0.03
L. Testis
Absolute | 1.57 ± 0.02*** | 1.57 ± 0.02 | 1.54 ± 0.02 | 1.58 ± 0.02 | 1.60 ± 0.03 | 1.65 ± 0.02*
Relative | 4.56 ± 0.07*** | 4.55 ± 0.07 | 4.67 ± 0.07 | 4.66 ± 0.07 | 4.78 ± 0.07 | 5.16 ± 0.07***
R. Testis
Absolute | 1.54 ± 0.02** | 1.53 ± 0.02 | 1.52 ± 0.02 | 1.49 ± 0.02 | 1.57 ± 0.02 | 1.59 ± 0.02
Relative | 4.47 ± 0.06*** | 4.45 ± 0.06 | 4.62 ± 0.06 | 4.41 ± 0.06 | 4.69 ± 0.06 | 4.98 ± 0.06***
L. Epididymis
Absolute | 0.48 ± 0.01** | 0.48 ± 0.01 | 0.49 ± 0.01 | 0.46 ± 0.01 | 0.49 ± 0.01 | 0.52 ± 0.01*
Relative | 1.37 ± 0.04*** | 1.40 ± 0.04 | 1.47 ± 0.04 | 1.36 ± 0.04 | 1.46 ± 0.04 | 1.61 ± 0.04***
R. Epididymis
Absolute | 0.47 ± 0.01 | 0.47 ± 0.01 | 0.47 ± 0.01 | 0.44 ± 0.01 | 0.48 ± 0.01 | 0.48 ± 0.01
Relative | 1.37 ± 0.04** | 1.35 ± 0.04 | 1.44 ± 0.04 | 1.31 ± 0.04 | 1.44 ± 0.04 | 1.51 ± 0.04*
Female
Necropsy Body Weight | 198 ± 5 | 202 ± 3 | 200 ± 3 | 196 ± 4 | 185 ± 3 | 169 ± 2
Heart
Absolute | 0.69 ± 0.02** | 0.72 ± 0.02 | 0.70 ± 0.02 | 0.70 ± 0.02 | 0.66 ± 0.02 | 0.65 ± 0.02
Relative | 3.49 ± 0.09** | 3.59 ± 0.09 | 3.50 ± 0.09 | 3.60 ± 0.09 | 3.60 ± 0.09 | 3.85 ± 0.09*
R. Kidney
Absolute | 0.73 ± 0.02***^c^ | 0.72 ± 0.02 | 0.72 ± 0.02 | 0.73 ± 0.02 | 0.69 ± 0.02 | 0.66 ± 0.02**
Relative | 3.68 ± 0.07**^c^ | 3.55 ± 0.06 | 3.60 ± 0.06 | 3.71 ± 0.06 | 3.72 ± 0.06 | 3.90 ± 0.06
Liver
Absolute | 5.15 ± 0.15***^c^ | 5.15 ± 0.14 | 5.21 ± 0.14 | 5.31 ± 0.14 | 5.68 ± 0.14 | 5.81 ± 0.14*
Relative | 25.87 ± 0.59***^c^ | 25.57 ± 0.56 | 26.06 ± 0.56 | 27.17 ± 0.56 | 30.66 ± 0.56*** | 34.48 ± 0.56***
Lung
Absolute | 0.93 ± 0.02** | 0.94 ± 0.02 | 0.92 ± 0.02 | 0.92 ± 0.02 | 0.89 ± 0.02 | 0.86 ± 0.02
Relative | 4.69 ± 0.12** | 4.68 ± 0.12 | 4.63 ± 0.12 | 4.72 ± 0.12 | 4.84 ± 0.12 | 5.08 ± 0.12
Thymus
Absolute | 0.17 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.17 ± 0.01
Relative | 0.86 ± 0.05 | 0.97 ± 0.05 | 0.89 ± 0.05 | 1.00 ± 0.05 | 0.98 ± 0.05 | 0.98 ± 0.05

^a^ Body weights, which are given in grams, were obtained just prior to euthanasia after an overnight fast and were generally lower than the animal removal weights for week 13 of the study reported in Appendix D, which were obtained prior to the fast.

^b^ Organ weights (absolute weights) are given in milligrams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight; necropsy body weights are given in grams. Values given as mean ± standard error. Asterisks denote significant dose trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^c^ n = 9.

Table E-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy Body Weight^a^ | 28.3 ± 0.6 | 28.2 ± 0.7 | 27.9 ± 0.7 | 28.0 ± 0.7 | 27.2 ± 0.7 | 26.4 ± 0.4
Heart^b^
Absolute | 195.83 ± 9.73* | 189.21 ± 9.73 | 199.50 ± 9.73 | 195.51 ± 9.73 | 181.64 ± 9.73 | 171.62 ± 9.73
Relative | 6.97 ± 0.30 | 6.66 ± 0.30 | 7.17 ± 0.30 | 6.99 ± 0.30 | 6.62 ± 0.30 | 6.49 ± 0.30
R. Kidney
Absolute | 234.72 ± 7.69 | 231.69 ± 7.69 | 229.73 ± 7.69 | 234.92 ± 7.69 | 242.53 ± 7.69 | 221.55 ± 7.69
Relative | 8.32 ± 0.17 | 8.18 ± 0.17 | 8.23 ± 0.17 | 8.40 ± 0.17 | 8.87 ± 0.17 | 8.39 ± 0.17
Liver
Absolute | 1,012.80 ± 35.13* | 1,033.46 ± 35.13 | 1,029.29 ± 35.13 | 1,042.96 ± 35.13 | 1,075.33 ± 35.13 | 1,115.0 ± 33.13
Relative | 35.86 ± 0.79*** | 36.52 ± 0.79 | 36.79 ± 0.79 | 37.29 ± 0.79 | 39.39 ± 0.79* | 42.20 ± 0.79***
Lung
Absolute | 222.63 ± 14.33* | 221.82 ± 14.33 | 211.36 ± 14.33 | 220.86 ± 14.33 | 204.03 ± 14.33 | 186.69 ± 14.33
Relative | 7.92 ± 0.44 | 7.83 ± 0.44 | 7.52 ± 0.44 | 7.88 ± 0.44 | 7.42 ± 0.44 | 7.05 ± 0.44
L. Testis
Absolute | 117.70 ± 2.64 | 114.47 ± 2.64 | 112.58 ± 2.64 | 114.59 ± 2.64 | 116.02 ± 2.64 | 113.37 ± 2.64
Relative | 4.18 ± 0.09* | .06 ± 0.09 | 4.04 ± 0.09 | 4.11 ± 0.09 | 4.26 ± 0.09 | 4.30 ± 0.09
R. Testis
Absolute | 117.59 ± 2.62 | 115.51 ± 2.62 | 113.82 ± 2.62 | 119.32 ± 2.62 | 118.16 ± 2.62 | 114.59 ± 2.62
Relative | 4.17 ± 0.09* | 4.09 ± 0.09 | 4.08 ± 0.09 | 4.28 ± 0.09 | 4.34 ± 0.09 | 4.35 ± 0.09
Thymus
Absolute | 27.12 ± 1.69 | 24.33 ± 1.78^c^ | 24.31 ± 1.69 | 23.18 ± 1.69 | 22.72 ± 1.69 | 23.99 ± 1.69
Relative | 0.96 ± 0.05 | 0.88 ± 0.06^c^ | 0.86 ± 0.05 | 0.83 ± 0.05 | 0.83 ± 0.05 | 0.91 ± 0.05
L. Epididymis
Absolute | 49.72 ± 2.17 | 49.73 ± 2.17 | 44.95 ± 2.17 | 47.80 ± 2.17 | 47.48 ± 2.17 | 44.54 ± 2.17
Relative | 1.77 ± 0.08 | 1.77 ± 0.08 | 1.61 ± 0.08 | 1.71 ± 0.08 | 1.75 ± 0.08 | 1.69 ± 0.08
R. Epididymis
Absolute | 46.45 ± 1.58 | 43.80 ± 1.58 | 43.06 ± 1.58 | 45.73 ± 1.58 | 44.77 ± 1.58 | 43.48 ± 1.58
Relative | 1.65 ± 0.06 | 1.55 ± 0.06 | 1.54 ± 0.06 | 1.64 ± 0.06 | 1.65 ± 0.06 | 1.65 ± 0.06
Female
Necropsy Body Weight | 21.9 ± 0.3 | 22.7 ± 0.4 | 21.3 ± 0.7^b^ | 21.6 ± 0.6 | 22.0 ± 0.4 | 22.2 ± 0.4
Heart
Absolute | 159.34 ± 7.37 | 147.80 ± 7.37 | 140.12 ± 7.77^c^ | 141.35 ± 7.37 | 149.74 ± 7.37 | 149.77 ± 7.37
Relative | 7.24 ± 0.29 | 6.55 ± 0.29 | 6.55 ± 0.30^c^ | 6.53 ± 0.29 | 6.83 ± 0.29 | 6.75 ± 0.29
R. Kidney
Absolute | 160.85 ± 3.93 | 174.87 ± 3.93 | 166.21 ± 4.14^c^ | 158.31 ± 3.93 | 169.67 ± 3.93 | 171.28 ± 3.93
Relative | 7.34 ± 0.13 | 7.74 ± 0.13 | 7.81 ± 0.14^c^ | 7.33 ± 0.13 | 7.73 ± 0.13 | 7.72 ± 0.13
Liver
Absolute | 826.43 ± 33.07*** | 864.17 ± 33.07 | 809.47 ± 34.86^c^ | 852.32 ± 33.07 | 851.06 ± 33.07 | 1,000.28 ± 33.07**
Relative | 37.71 ± 0.92*** | 38.07 ± 0.92 | 37.71 ± 0.97^c^ | 39.46 ± 0.92 | 38.69 ± 0.92 | 44.99 ± 0.92***
Lung
Absolute | 199.10 ± 13.85 | 203.02 ± 13.85 | 179.13 ± 14.60^c^ | 211.78 ± 13.85 | 180.84 ± 13.85 | 178.86 ± 13.85
Relative | 9.05 ± 0.51 | 8.92 ± 0.51 | 8.36 ± 0.54^c^ | 9.71 ± 0.51 | 8.21 ± 0.51 | 8.03 ± 0.51
Thymus
Absolute | 24.89 ± 2.26 | 27.79 ± 2.26 | 26.31 ± 2.38^c^ | 27.97 ± 2.26 | 23.39 ± 2.26 | 29.86 ± 2.26
Relative | 1.13 ± 0.09 | 1.22 ± 0.09 | 1.21 ± 0.09^c^ | 1.27 ± 0.09 | 1.06 ± 0.09 | 1.34 ± 0.09

^a^ Body weights, which are given in grams, were obtained just prior to euthanasia after an overnight fast and were generally lower than the animal removal weights for week 13 of the study reported in Appendix D which were obtained prior to the fast.

^b^ Organ weights (absolute weights) are given in milligrams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight; necropsy body weights are given in grams. Values given as mean ± standard error. Asterisks denote significant dose trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^c^ n = 9.