# Appendix D Body Weights

Table D-1 Body Weights of Male Rats in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 194.4 ± 5.1 | 10 | 196.2 ± 3.9 | | 10 | 195.4 ± 5.1 | | 10 | 194.5 ± 3.8 | | 10 | 197.1 ± 5.5 | | 10 | 195.3 ± 4.3
1 | 10 | 218.9 ± 4.8** | 10 | 220.0 ± 4.1 | 100.5 | 10 | 216.9 ± 5.2 | 99.1 | 10 | 218.8 ± 3.8 | 100.0 | 10 | 219.2 ± 5.1 | 100.1 | 10 | 212.4 ± 3.5* | 97.0
2 | 10 | 239.5 ± 5.2* | 10 | 240.5 ± 4.3 | 100.4 | 10 | 234.9 ± 5.2 | 98.1 | 10 | 237.8 ± 4.8 | 99.3 | 10 | 238.3 ± 4.8 | 99.5 | 10 | 232.1 ± 3.8* | 96.9
3 | 10 | 258.0 ± 5.4*** | 10 | 259.3 ± 4.6 | 100.5 | 10 | 251.0 ± 5.1 | 97.3 | 10 | 255.6 ± 4.2 | 99.1 | 10 | 254.8 ± 4.1 | 98.8 | 10 | 243.7 ± 3.4*** | 94.5
4 | 10 | 273.4 ± 5.0*** | 10 | 274.0 ± 4.9 | 100.2 | 10 | 265.3 ± 5.2 | 97.0 | 10 | 270.9 ± 4.4 | 99.1 | 10 | 270.1 ± 4.9 | 98.8 | 10 | 258.2 ± 3.3*** | 94.4
5 | 10 | 289.1 ± 5.3*** | 10 | 287.8 ± 5.2 | 99.6 | 10 | 279.6 ± 5.5 | 96.7 | 10 | 284.9 ± 4.4 | 98.5 | 10 | 283.3 ± 5.3 | 98.0 | 10 | 270.2 ± 3.0*** | 93.5
6 | 10 | 302.3 ± 5.3*** | 10 | 301.8 ± 5.3 | 99.8 | 10 | 291.0 ± 6.0* | 96.3 | 10 | 297.7 ± 3.8 | 98.5 | 10 | 296.1 ± 5.1 | 97.9 | 10 | 285.0 ± 3.2*** | 94.3
7 | 10 | 314.9 ± 4.7*** | 10 | 310.7 ± 4.3 | 98.7 | 10 | 300.3 ± 6.4** | 95.4 | 10 | 310.7 ± 4.8 | 98.7 | 10 | 306.8 ± 5.1 | 97.4 | 10 | 294.2 ± 3.5*** | 93.4
8 | 10 | 323.9 ± 4.9*** | 10 | 321.2 ± 4.1 | 99.2 | 10 | 307.3 ± 6.2** | 94.9 | 10 | 317.0 ± 4.6 | 97.9 | 10 | 314.5 ± 4.8 | 97.1 | 10 | 301.0 ± 3.1*** | 92.9
9 | 10 | 334.0 ± 5.5*** | 10 | 331.5 ± 4.7 | 99.3 | 10 | 319.0 ± 6.4* | 95.5 | 10 | 327.0 ± 5.4 | 97.9 | 10 | 325.8 ± 5.0 | 97.5 | 10 | 307.7 ± 3.1*** | 92.1
10 | 10 | 341.0 ± 5.4*** | 10 | 340.0 ± 4.5 | 99.7 | 10 | 324.9 ± 6.6* | 95.3 | 10 | 337.4 ± 4.7 | 98.9 | 10 | 335.0 ± 5.5 | 98.2 | 10 | 317.1 ± 2.9*** | 93.0
11 | 10 | 347.1 ± 5.0*** | 10 | 347.3 ± 4.3 | 100.1 | 10 | 331.2 ± 6.4** | 95.4 | 10 | 341.5 ± 4.6 | 98.4 | 10 | 341.6 ± 5.5 | 98.4 | 10 | 324.2 ± 3.3*** | 93.4
12 | 10 | 352.7 ± 5.6*** | 10 | 353.8 ± 4.4 | 100.3 | 10 | 337.8 ± 6.6 | 95.8 | 10 | 347.5 ± 4.5 | 98.5 | 10 | 345.2 ± 6.3 | 97.9 | 10 | 327.6 ± 4.3*** | 92.9
13 | 10 | 359.4 ± 5.5*** | 10 | 357.1 ± 5.1 | 99.4 | 10 | 342.6 ± 6.1* | 95.3 | 10 | 353.0 ± 4.2 | 98.2 | 10 | 350.5 ± 6.0 | 97.5 | 10 | 334.2 ± 3.5*** | 93.0
Mean for Weeks
1–13 | | 305.2 ± 3.2*** | | 302.8 ± 3.2 | 99.2 | | 292.5 ± 3.2* | 95.8 | | 300.9 ± 3.2 | 98.6 | | 297.0 ± 3.2 | 97.3 | | 285.4 ± 3.2*** | 93.5

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant dose trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^d^ Mean weight as percentage of control.

Table D-2 Body Weights of Female Rats in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | 30 ppm | | | 60 ppm | | | 120 ppm | | | 360 ppm | | | 720 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 140.4 ± 1.8 | 10 | 141.5 ± 1.6 | | 10 | 144.5 ± 2.0 | | 10 | 139.3 ± 2.0 | | 10 | 139.6 ± 2.2 | | 10 | 141.5 ± 2.4
1 | 10 | 151.5 ± 2.4*** | 10 | 151.2 ± 2.2 | 99.8 | 10 | 154.3 ± 2.0 | 101.8 | 10 | 150.7 ± 2.3 | 99.5 | 10 | 148.9 ± 1.9 | 98.3 | 10 | 145.2 ± 1.6*** | 95.8
2 | 10 | 161.0 ± 2.6*** | 10 | 160.4 ± 2.8 | 99.6 | 10 | 165.1 ± 2.0 | 102.5 | 10 | 159.0 ± 2.7 | 98.8 | 10 | 157.8 ± 2.4 | 98.0 | 10 | 151.0 ± 1.7*** | 93.8
3 | 10 | 170.2 ± 3.0*** | 10 | 170.2 ± 2.6 | 100.0 | 10 | 173.5 ± 2.3 | 101.9 | 10 | 166.3 ± 2.9 | 97.7 | 10 | 166.3 ± 3.0 | 97.7 | 10 | 154.8 ± 1.8*** | 91.0
4 | 10 | 177.6 ± 2.7*** | 10 | 177.0 ± 2.6 | 99.7 | 10 | 180.7 ± 2.2 | 101.7 | 10 | 174.7 ± 2.4 | 98.4 | 10 | 173.3 ± 2.9 | 97.6 | 10 | 160.4 ± 2.0*** | 90.3
5 | 10 | 184.3 ± 3.5*** | 10 | 184.8 ± 2.8 | 100.3 | 10 | 187.3 ± 2.8 | 101.6 | 10 | 181.5 ± 3.3 | 98.5 | 10 | 177.4 ± 3.2 | 96.3 | 10 | 165.2 ± 2.1*** | 89.6
6 | 10 | 189.0 ± 3.9*** | 10 | 189.5 ± 3.1 | 100.3 | 10 | 193.1 ± 2.8 | 102.2 | 10 | 186.4 ± 3.4 | 98.6 | 10 | 180.6 ± 3.1* | 95.6 | 10 | 168.3 ± 2.4*** | 89.0
7 | 10 | 195.0 ± 4.3*** | 10 | 193.7 ± 3.4 | 99.3 | 10 | 197.5 ± 3.0 | 101.3 | 10 | 192.2 ± 3.6 | 98.6 | 10 | 187.0 ± 3.5 | 95.9 | 10 | 172.3 ± 1.9*** | 88.4
8 | 10 | 198.1 ± 4.3*** | 10 | 198.7 ± 3.5 | 100.3 | 10 | 200.7 ± 3.4 | 101.3 | 10 | 195.2 ± 4.0 | 98.5 | 10 | 188.8 ± 3.0* | 95.3 | 10 | 174.7 ± 2.3*** | 88.2
9 | 10 | 202.0 ± 4.4*** | 10 | 202.1 ± 3.6 | 100.0 | 10 | 204.1 ± 2.6 | 101.0 | 10 | 198.9 ± 4.0 | 98.5 | 10 | 193.5 ± 3.3* | 95.8 | 10 | 176.8 ± 2.3*** | 87.5
10 | 10 | 205.5 ± 4.6*** | 10 | 206.9 ± 4.1 | 100.7 | 10 | 205.8 ± 3.2 | 100.1 | 10 | 202.5 ± 4.3 | 98.5 | 10 | 194.8 ± 3.7* | 94.8 | 10 | 177.2 ± 2.5*** | 86.2
11 | 10 | 206.2 ± 4.5*** | 10 | 208.2 ± 4.1 | 101.0 | 10 | 205.2 ± 2.7 | 99.5 | 10 | 203.0 ± 4.0 | 98.4 | 10 | 194.5 ± 3.0** | 94.3 | 10 | 180.0 ± 3.3*** | 87.3
12 | 10 | 207.3 ± 4.4*** | 10 | 210.4 ± 3.2 | 101.5 | 10 | 207.9 ± 3.1 | 100.3 | 10 | 204.1 ± 4.0 | 98.5 | 10 | 194.6 ± 3.4** | 93.9 | 10 | 180.2 ± 2.3*** | 86.9
13 | 10 | 209.1 ± 4.4*** | 10 | 212.6 ± 3.2 | 101.7 | 10 | 210.2 ± 3.6 | 100.5 | 10 | 205.5 ± 4.0 | 98.3 | 10 | 195.8 ± 3.2** | 93.6 | 10 | 178.7 ± 2.1*** | 85.5
Mean for Weeks
1–13 | | 189.7 ± 1.7*** | | 189.3 ± 1.7 | 99.8 | | 188.2 ± 1.7 | 99.2 | | 187.8 ± 1.7 | 99.0 | | 182.4 ± 1.7* | 96.2 | | 167.7 ± 1.7*** | 88.4

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant dose trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^d^ Mean weight as percentage of control.

Table D-3 Body Weights of Male Mice in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 22.4 ± 0.5 | 10 | 22.0 ± 0.6 | | 10 | 22.1 ± 0.7 | | 10 | 22.2 ± 0.6 | | 10 | 22.2 ± 0.5 | | 10 | 21.5 ± 0.4
1 | 10 | 23.0 ± 0.4 | 10 | 23.2 ± 0.4 | 100.9 | 10 | 23.2 ± 0.5 | 100.9 | 10 | 23.4 ± 0.6 | 101.7 | 10 | 23.1 ± 0.4 | 100.4 | 10 | 22.5 ± 0.3 | 97.8
2 | 10 | 23.7 ± 0.4 | 10 | 24.1 ± 0.4 | 101.7 | 10 | 24.4 ± 0.4 | 103.0 | 10 | 24.5 ± 0.5 | 103.4 | 10 | 24.0 ± 0.7 | 101.3 | 10 | 23.1 ± 0.3 | 97.5
3 | 10 | 25.0 ± 0.5* | 10 | 25.3 ± 0.4 | 101.2 | 10 | 25.2 ± 0.5 | 100.8 | 10 | 25.3 ± 0.6 | 101.2 | 10 | 25.1 ± 0.5 | 100.4 | 10 | 23.8 ± 0.5 | 95.2
4 | 10 | 25.5 ± 0.4* | 10 | 26.1 ± 0.4 | 102.4 | 10 | 26.1 ± 0.4 | 102.4 | 10 | 25.9 ± 0.6 | 101.6 | 10 | 25.5 ± 0.6 | 100.0 | 10 | 24.5 ± 0.5 | 96.1
5 | 10 | 26.4 ± 0.3** | 10 | 27.5 ± 0.6* | 104.2 | 10 | 26.3 ± 0.5 | 99.6 | 10 | 26.9 ± 0.6 | 101.9 | 10 | 26.7 ± 0.5 | 101.1 | 10 | 25.2 ± 0.5 | 95.5
6 | 10 | 27.5 ± 0.4** | 10 | 28.2 ± 0.4 | 102.5 | 10 | 27.6 ± 0.5 | 100.4 | 10 | 28.1 ± 0.8 | 102.2 | 10 | 26.8 ± 0.5 | 97.5 | 10 | 26.0 ± 0.4 | 94.5
7 | 10 | 27.9 ± 0.5** | 10 | 28.5 ± 0.4 | 102.2 | 10 | 28.3 ± 0.5 | 101.4 | 10 | 28.3 ± 0.6 | 101.4 | 10 | 27.5 ± 0.3 | 98.6 | 10 | 26.6 ± 0.5 | 95.3
8 | 10 | 28.4 ± 0.5** | 10 | 28.8 ± 0.4 | 101.4 | 10 | 28.7 ± 0.5 | 101.1 | 10 | 28.9 ± 0.6 | 101.8 | 10 | 27.8 ± 0.5 | 97.9 | 10 | 26.7 ± 0.3 | 94.0
9 | 10 | 29.0 ± 0.4** | 10 | 29.6 ± 0.4 | 102.1 | 10 | 29.2 ± 0.6 | 100.7 | 10 | 29.2 ± 0.5 | 100.7 | 10 | 27.6 ± 0.7 | 95.2 | 10 | 27.5 ± 0.5 | 94.8
10 | 10 | 29.4 ± 0.5 | 10 | 29.3 ± 0.7 | 99.7 | 10 | 29.3 ± 0.6 | 99.7 | 10 | 29.4 ± 0.6 | 100.0 | 10 | 28.4 ± 0.5 | 96.6 | 10 | 28.1 ± 0.4 | 95.6
11 | 10 | 29.8 ± 0.4** | 10 | 30.3 ± 0.7 | 101.7 | 10 | 30.3 ± 0.5 | 101.7 | 10 | 30.4 ± 0.5 | 102.0 | 10 | 28.7 ± 0.4 | 96.3 | 10 | 28.7 ± 0.4 | 96.3
12 | 10 | 30.2 ± 0.6 | 10 | 30.2 ± 0.5 | 100.0 | 10 | 29.8 ± 0.5 | 98.7 | 10 | 30.2 ± 0.5 | 100.0 | 10 | 29.2 ± 0.6 | 96.7 | 10 | 28.8 ± 0.7 | 95.4
13 | 10 | 30.7 ± 0.7 | 10 | 30.9 ± 0.5 | 100.7 | 10 | 30.6 ± 0.5 | 99.7 | 10 | 31.0 ± 0.8 | 101.0 | 10 | 29.8 ± 0.7 | 97.1 | 10 | 29.5 ± 0.4 | 96.1
Mean for Weeks
1–13 | | 27.2 ± 0.2*** | | 27.9 ± 0.2 | 102.5 | | 27.6 ± 0.2 | 101.5 | | 27.7 ± 0.2 | 101.8 | | 26.9 ± 0.2 | 98.8 | | 26.6 ± 0.2 | 98.0

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant dose trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**); p ≤ 0.001 (***).

^d^ Mean weight as percentage of control.

Table D-4 Body Weights of Female Mice in the Three-month Feed Study of (+)-Usnic Acid

Week^a^ | 0 ppm | | 15 ppm | | | 30 ppm | | | 60 ppm | | | 180 ppm | | | 360 ppm
Week^a^ | N^b^ | Mean ± SE^c^ | N | Mean ± SE | Pct^d^ | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct | N | Mean ± SE | Pct
0 | 10 | 17.8 ± 0.2 | 10 | 18.1 ± 0.3 | | 10 | 18.3 ± 0.3 | | 10 | 17.3 ± 0.3 | | 10 | 18.0 ± 0.2 | | 10 | 18.5 ± 0.3
1 | 10 | 18.9 ± 0.2 | 10 | 19.4 ± 0.3 | 102.6 | 10 | 19.3 ± 0.3 | 102.1 | 10 | 18.3 ± 0.3 | 96.8 | 10 | 19.2 ± 0.2 | 101.6 | 10 | 19.7 ± 0.3 | 104.2
2 | 10 | 19.7 ± 0.2 | 10 | 19.9 ± 0.2 | 101.0 | 10 | 19.9 ± 0.3 | 101.0 | 10 | 19.4 ± 0.2 | 98.5 | 10 | 20.1 ± 0.3 | 102.0 | 10 | 20.4 ± 0.3 | 103.6
3 | 10 | 20.4 ± 0.2 | 10 | 20.5 ± 0.2 | 100.5 | 10 | 20.4 ± 0.3 | 100.0 | 10 | 20.1 ± 0.3 | 98.5 | 10 | 20.8 ± 0.3 | 102.0 | 10 | 20.7 ± 0.3 | 101.5
4 | 10 | 21.0 ± 0.1 | 10 | 20.9 ± 0.4 | 99.5 | 9 | 21.1 ± 0.4 | 100.5 | 10 | 20.7 ± 0.3 | 98.6 | 10 | 21.0 ± 0.3 | 100.0 | 10 | 21.3 ± 0.4 | 101.4
5 | 10 | 21.9 ± 0.3* | 10 | 22.0 ± 0.3 | 100.5 | 9 | 21.1 ± 0.4* | 96.3 | 10 | 21.3 ± 0.3 | 97.3 | 10 | 21.5 ± 0.3 | 98.2 | 10 | 21.4 ± 0.3 | 97.7
6 | 10 | 22.0 ± 0.1* | 10 | 22.0 ± 0.3 | 100.0 | 9 | 21.3 ± 0.4* | 96.8 | 10 | 21.3 ± 0.3 | 96.8 | 10 | 21.8 ± 0.4 | 99.1 | 10 | 21.6 ± 0.3* | 98.2
7 | 10 | 22.4 ± 0.2* | 10 | 22.6 ± 0.3 | 100.9 | 9 | 22.2 ± 0.4 | 99.1 | 10 | 21.8 ± 0.3 | 97.3 | 10 | 22.7 ± 0.4 | 101.3 | 10 | 22.0 ± 0.5 | 98.2
8 | 10 | 22.9 ± 0.3** | 10 | 23.3 ± 0.4 | 101.7 | 9 | 23.0 ± 0.5 | 100.4 | 10 | 21.9 ± 0.3 | 95.6 | 10 | 22.3 ± 0.4 | 97.4 | 10 | 22.5 ± 0.4 | 98.3
9 | 10 | 22.9 ± 0.3 | 10 | 23.2 ± 0.4 | 101.3 | 9 | 22.8 ± 0.7 | 99.6 | 10 | 22.2 ± 0.2 | 96.9 | 10 | 22.8 ± 0.3 | 99.6 | 10 | 22.6 ± 0.5 | 98.7
10 | 10 | 23.3 ± 0.3 | 10 | 23.5 ± 0.4 | 100.9 | 9 | 23.1 ± 0.4 | 99.1 | 10 | 22.5 ± 0.3 | 96.6 | 10 | 23.0 ± 0.3 | 98.7 | 10 | 23.6 ± 0.6 | 101.3
11 | 10 | 23.5 ± 0.2 | 10 | 23.9 ± 0.4 | 101.7 | 9 | 23.3 ± 0.3 | 99.1 | 10 | 22.8 ± 0.3 | 97.0 | 10 | 23.5 ± 0.3 | 100.0 | 10 | 23.5 ± 0.5 | 100.0
12 | 10 | 24.1 ± 0.4 | 10 | 23.5 ± 0.3 | 97.5 | 9 | 24.1 ± 0.5 | 100.0 | 10 | 23.5 ± 0.3 | 97.5 | 10 | 24.0 ± 0.5 | 99.6 | 10 | 24.5 ± 0.5 | 101.7
13 | 10 | 24.6 ± 0.4 | 10 | 24.3 ± 0.4 | 98.8 | 9 | 24.1 ± 0.6 | 98.0 | 10 | 23.8 ± 0.4 | 96.7 | 10 | 24.6 ± 0.3 | 100.0 | 10 | 24.4 ± 0.4 | 99.2
Mean for Weeks
1–13 | | 22.2 ± 0.1* | | 22.2 ± 0.1 | 99.6 | | 21.8 ± 0.1 | 98.0 | | 22.1 ± 0.1 | 99.2 | | 22.1 ± 0.1 | 99.3 | | 21.8 ± 0.1* | 97.8

^a^ Measured after each week of exposure.

^b^ N = number of animals.

^c^ Body weight (g) as mean ± standard error. Asterisks denote significant dose trend (control column) or significant pairwise comparison to control group (Dunnett’s test, other columns): p ≤ 0.05 (*); p ≤ 0.01 (**).

^d^ Mean weight as percentage of control.