# Appendix B Genetic Toxicology Studies

## B.1 Background

(+)-Usnic acid has been tested for genotoxicity in several in vitro systems. It showed no mutagenicity in tested strains including TA98 and TA100 without or with S9 addition at a highest dose of 200 µg per plate.^90^ NTP studies confirmed that (+)-usnic acid was negative in Ames tests with S. typhimurium strains TA98 and TA100 and E. coli strain WP2 uvrA (pkM101), with and without the addition of rat liver S9.^104^ (+)-Usnic acid was evaluated for genotoxicity in human lymphocytes in vitro using the cytokinesis-blocked micronucleus (CBMN) assay.^105^ Although the number of micronuclei was higher in the lymphocytes treated with (+)-usnic acid in comparison to control lymphocytes, the induction was not significant statistically. The authors concluded that (+)-usnic acid was nongenotoxic as shown by the absence of significant micronucleus induction in human lymphocytes. Oral administration of a single dose of either 100 or 200 mg/kg usnic acid caused a slight increase in micronucleated erythrocytes in the mice 24 and 48 hours after treatment, which did not reach statistical significance and returned to control levels by 72 hours.^102^

The objective of this genetic toxicology evaluation was to determine whether in vivo exposure to (+)-usnic acid would significantly increase micronuclei formation in peripheral blood from mice that were exposed to (+)-usnic acid for the 2-week acute toxicity studies that were run in conjunction with this 3-month study.

## B.2 Methods

Peripheral blood was collected at sacrifice from B6C3F1/Nctr mice evaluated for the 2-week acute toxicity studies (Appendix J), and aliquots were diluted with anticoagulant, fixed in cold (−80°C) methanol, and stored at –85°C. The fixed blood samples were shipped to Litron Laboratories (Rochester, NY) on dry ice for analysis. Micronucleated cells were identified and quantified using a MicroFlow PLUS mouse kit from Litron Laboratories.^129,130^ Briefly, reticulocytes were identified by fluorescein isothiocyanate-labeled antibodies against the CD71 mouse surface antigen, platelets were identified by phycoerythrin-labeled antibodies against CD61 antigen, and DNA, including micronuclei, was stained with propidium iodide. Data provided by Litron was compiled in the form of sorted spreadsheets of differences in reticulocyte micronucleus frequency between dose groups, and as audited study reports, which have been added to the Study Archive. The spreadsheet data were then analyzed at NCTR in SAS (version 9.1, TS level 1M3) to produce means, standard error values and significant differences between dose groups via a Dunnett test evaluation and a linear trend test run under the SAS General Linear Models program.

## B.3 Results

The micronucleus frequencies for male and female B6C3F1/Nctr mice exposed to either 600 or 1,200 ppm (+)-usnic acid in feed for 14 days are shown in Table B-1. In males, (+)-usnic acid exposure did not significantly change the percentage of total reticulocytes in the samples (% RET), but significantly increased the percentage of micronucleated normochromatic erythrocytes (% NCE) at the 600 ppm dose level and the percentage of micronucleated reticulocytes (% micronucleated RET) at both the 600 and 1,200 ppm levels with a significant exposure trend. In female B6C3F1/Nctr mice, (+)-usnic acid exposure caused a large statistically significant decrease in % RET at the 1,200 ppm exposure level and significantly increased both the % NCE and % micronucleated RET at the 600 ppm dose level but not at the 1,200 ppm level. The decrease in reticulocyte numbers at the high dose could reflect bone marrow toxicity. In both sexes, the increases in % NCE and % micronucleated RET were relatively small compared to certain other genotoxins. For example, perinatal exposure to 3’-azido-3’deoxythymidine (zidovudine) was reported to increase % NCE and % micronucleated RET 60- and 30-fold respectively in 10-day old mice B6C3F1/NTac mice.^131^

Table B-1 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in Mice in the Two-week Feed Study of (+)-Usnic Acid

| % RET | % Micronucleated NCE | % Micronucleated RET
Male
Vehicle Control | 5^a^ | 5 | 5
Mean ± standard error | 1.7 ± 0.07 | 0.15 ± 0.005 | 0.28 ± 0.025
Trend test p value | p = 0.18^b^ | p = 0.26 | p ≤ 0.001
600 ppm | 5 | 5 | 5
Mean ± standard error | 2.2 ± 0.13 | 0.22 ± 0.008 | 0.61 ± 0.045
Dunnett’s test p value | p = 0.92 | p ≤ 0.001 | p ≤ 0.001
1,200 ppm | 4 | 4 | 3
Mean ± standard error | 4.3 ± 2.2 | 0.15 ± 0.005 | 0.88 ± 0.061
Dunnett’s test p value | p = 0.21 | p = 0.41 | p ≤ 0.001
Female
Vehicle Control | 5 | 5 | 5
Mean ± standard error | 1.8 ± 0.12 | 0.12 ± 0.003 | 0.21 ± 0.015
Trend test p value | p ≤ 0.001 | p = 0.010 | –
600 ppm | 5 | 5 | 5
Mean ± standard error | 2.3 ± 0.19 | 0.16 ± 0.002 | 0.40 ± 0.023
Dunnett’s test p value | p = 0.11 | p = 0.002 | p ≤ 0.001
1,200 ppm | 3 | 3
Mean ± standard error | 0.04 ± 0.03 | 0.09 ± 0.015 | ND^c^
Dunnett’s test p value | p ≤ 0.001 | p = 0.019 | –

RET = reticulocytes expressed as percentages of total red blood cells; NCE = normochromatic erythrocytes

^a^ Number examined.

^b^ p values listed under the control group values denote trend test significance, and those beneath the dosed group values denote significance of Dunnett test pairwise comparisons between the feed controls and that dosed group. Two-tailed Dunnett tests were used.

^c^ ND = not detected due to low reticulocyte concentration.