# Appendix A Summary of Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths | 0 | 0 | 0 | 0 | 0 | 0
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10)^a^ | (10) | (10) | (10) | (10) | (10)
Angiectasis | 0 | 0 | 0 | 1 (10%) | 0 | 0
Eosinophilic focus | 0 | 0 | 0 | 0 | 1 (10%) | 0
Inflammation, chronic | 0 | 1 (10%) | 3 (30%) | 3 (30%) | 8 (80%) | 10 (100%)
Hepatocellular degeneration | 1 (10%) | 0 | 3 (30%) | 4 (40%) | 10 (100%) | 10 (100%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Acinus, degeneration | 0 | –^b^ | – | – | – | 1 (10%)
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 9 (90%) | – | – | – | – | 7 (70%)
Endocrine System
Pituitary Gland | (10) | (0) | (0) | (0) | (0) | (10)
Pars distalis, cyst | 2 (20%) | – | – | – | – | 0
Pars intermedia, cyst | 0 | – | – | – | – | 1 (10%)
Thyroid Gland | (10) | (0) | (0) | (0) | (0) | (10)
Ectopic thymus | 4 (40%) | – | – | – | – | 1 (10%)
General Body System
None
Genital System
Preputial Gland | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, suppurative | 2 (20%) | – | – | – | – | 6 (60%)
Inflammation, chronic active | 1 (10%) | – | – | – | – | 1 (10%)
Duct, dilatation | 0 | – | – | – | – | 4 (40%)
Prostate | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, suppurative | 1 (10%) | – | – | – | – | 0
Hematopoietic System
Lymph Node, Mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, plasma cell | 0 | – | – | – | – | 1 (10%)
Lymph Node, Mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Hyperplasia, lymphoid | 1 (10%) | – | – | – | – | 2 (20%)
Infiltration cellular, mast cell | 8 (80%) | – | – | – | – | 7 (70%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, histiocyte | 0 | – | – | – | – | 1 (10%)
Special Senses System
None
Urinary System
Kidney | (10) | (0) | (0) | (10) | (10) | (10)
Hydronephrosis | 0 | – | – | – | 2 (20%) | 5 (50%)
Nephropathy | 10 (100%) | – | – | 10 (100%) | 10 (100%) | 9 (90%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-2 Statistical Analysis of Nonneoplastic Lesions in Male Rats in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Liver
Hepatocellular Degeneration
Overall rate^a^ | 1/10 (10.0%) | 0/10 (0.0%) | 3/10 (30.0%) | 4/10 (40.0%) | 10/10 (100.0%) | 10/10 (100.0%)
Terminal rate^b^ | 1/10 (10.0%) | 0/10 (0.0%) | 3/10 (30.0%) | 4/10 (40.0%) | 10/10 (100.0%) | 10/10 (100.0%)
First incidence (days)^c^ | 90 (T) | –^d^ | 90 (T) | 90 (T) | 90 (T) | 90 (T)
CAFÉ p value^e^ | p ≤ 0.001 | p = 0.500N | p = 0.291 | p = 0.152 | p ≤ 0.001 | p ≤ 0.001
Average severity^f^ | 1.0 | – | 1.0 | 1.3 | 1.9 | 3.6
Inflammation
Overall rate | 0/10 (0.0%) | 1/10 (10.0%) | 3/10 (30.0%) | 3/10 (30.0%) | 8/10 (80.0%) | 10/10 (100.0%)
Terminal rate | 0/10 (0.0%) | 1/10 (10.0%) | 3/10 (30.0%) | 3/10 (30.0%) | 8/10 (80.0%) | 10/10 (100.0%)
First incidence (days) | – | 90 (T) | 90 (T) | 90 (T) | 90 (T) | 90 (T)
CAFÉ p value | p ≤ 0.001 | p = 0.500 | p = 0.105 | p = 0.105 | p ≤ 0.001 | p ≤ 0.001
Average severity | – | 1.0 | 1.0 | 1.0 | 1.3 | 1.3
Heart
Cardiomyopathy
Overall rate | 9/10 (90.0%) | – | – | – | – | 7/10 (70.0%)
Terminal rate | 9/10 (90.0%) | – | – | – | – | 7/10 (70.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.291N | – | – | – | – | p = 0.291N
Average severity | 1.3 | – | – | – | – | 1.3
Pituitary Gland
Pars Distalis Cyst
Overall rate | 2/10 (20.0%) | – | – | – | – | 0/10 (0.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | – | 0/10 (0.0%)
First incidence (days) | 90 (T) | – | – | – | – | –
CAFÉ p value | p = 0.237N | – | – | – | – | p = 0.237N
Average severity | 1.5 | – | – | – | – | –
Thyroid Gland
Ectopic Thymus
Overall rate | 4/10 (40.0%) | – | – | – | – | 1/10 (10.0%)
Terminal rate | 4/10 (40.0%) | – | – | – | – | 1/10 (10.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.152N | – | – | – | – | p = 0.152N
Average severity | 5.0 | – | – | – | – | 5.0
Preputial Gland
Duct Dilatation
Overall rate | 0/10 (0.0%) | – | – | – | – | 4/10 (40.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | – | 4/10 (40.0%)
First incidence (days) | – | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.043 | – | – | – | – | p = 0.043
Average severity | – | – | – | – | – | 3.8
Suppurative Inflammation
Overall rate | 2/10 (20.0%) | – | – | – | – | 6/10 (60.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | – | 6/10 (60.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.085 | – | – | – | – | p = 0.085
Average severity | 3.0 | – | – | – | – | 2.5
Mesenteric Lymph Node
Hyperplasia
Overall rate | 1/10 (10.0%) | – | – | – | – | 2/10 (20.0%)
Terminal rate | 1/10 (10.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500 | – | – | – | – | p = 0.500
Average severity | 2.0 | – | – | – | – | 2.0
Infiltration Cellular
Overall rate | 8/10 (80.0%) | – | – | – | – | 7/10 (70.0%)
Terminal rate | 80/10 (80.0%) | – | – | – | – | 7/10 (70.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500N | – | – | – | – | p = 0.500N
Average severity | 1.8 | – | – | – | – | 2.3
Kidney
Hydronephrosis
Overall rate | 0/10 (0.0%) | – | – | 0/10 (0.0%) | 2/10 (20.0%) | 5/10 (50.0%)
Terminal rate | 0/10 (0.0%) | – | – | 0/10 (0.0%) | 2/10 (20.0%) | 5/10 (50.0%)
First incidence (days) | – | – | – | – | 90 (T) | 90 (T)
CAFÉ p value | p = 0.001 | – | – | – | p = 0.237 | p = 0.016
Average severity | – | – | – | – | 1.5 | 1.4
Nephropathy
Overall rate | 10/10 (100.0%) | – | – | 10/10 (100.0%) | 10/10 (100.0%) | 9/10 (90.0%)
Terminal rate | 10/10 (100.0%) | – | – | 10/10 (100.0%) | 10/10 (100.0%) | 9/10 (90.0%)
First incidence (days) | 90 (T) | – | – | 90 (T) | 90 (T) | 90 (T)
CAFÉ p value | p = 0.250N | – | – | – | – | p = 0.500N
Average severity | 1.3 | – | – | 1.0 | 1.0 | 1.2

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Observed incidence at terminal sacrifice.

^c^ Time to first lesion in days. T indicates terminal sacrifice.

^d^ Indicates no data were collected.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with dose. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths | 0 | 0 | 0 | 0 | 0 | 0
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10)^a^ | (0) | (0) | (0) | (0) | (10)
Angiectasis | 0 | –^b^ | – | – | – | 1 (10%)
Bile duct, hyperplasia | 0 | – | – | – | – | 1 (10%)
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 7 (70%) | – | – | – | – | 7 (70%)
Endocrine System
Thyroid Gland | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 0 | – | – | – | – | 1 (10%)
Ectopic thymus | 1 (10%) | – | – | – | – | 3 (30%)
Ultimobranchial cyst | 0 | – | – | – | – | 1 (10%)
General Body System
None
Genital System
Clitoral Gland | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, lymphocyte | 3 (30%) | – | – | – | – | 3 (30%)
Inflammation, suppurative | 1 (10%) | – | – | – | – | 1 (10%)
Inflammation, chronic active | 2 (20%) | – | – | – | – | 2 (20%)
Duct, dilatation | 0 | – | – | – | – | 2 (20%)
Uterus | (10) | (0) | (0) | (0) | (0) | (10)
Lumen, dilatation | 3 (30%) | – | – | – | – | 1 (10%)
Hematopoietic System
Lymph Node, Mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Hyperplasia, lymphoid | 3 (30%) | – | – | – | – | 1 (10%)
Infiltration cellular, mast cell | 9 (90%) | – | – | – | – | 10 (100%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, histiocyte | 1 (10%) | – | – | – | – | 1 (10%)
Special Senses System
Harderian Gland | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, lymphocyte | 3 (30%) | – | – | – | – | 0
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 2 (20%) | – | – | – | – | 1 (10%)
Mineralization | 10 (100%) | – | – | – | – | 10 (100%)
Nephropathy | 2 (20%) | – | – | – | – | 10 (100%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-4 Statistical Analysis of Nonneoplastic Lesions in Female Rats in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 30 ppm | 60 ppm | 120 ppm | 360 ppm | 720 ppm
Heart
Cardiomyopathy
Overall rate^a^ | 7/10 (70.0%) | –^b^ | – | – | – | 7/10 (70.0%)
Terminal rate^c^ | 7/10 (70.0%) | – | – | – | – | 7/10 (70.0%)
First incidence (days)^d^ | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value^e^ | p = 0.686 | – | – | – | – | p = 0.686
Average severity^f^ | 1.1 | – | – | – | – | 1.4
Thyroid Gland
Ectopic Thymus
Overall rate | 1/10 (10.0%) | – | – | – | – | 3/10 (30.0%)
Terminal rate | 1/10 (10.0%) | – | – | – | – | 3/10 (30.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.291 | – | – | – | – | p = 0.291
Average severity | 5.0 | – | – | – | – | 5.0
Clitoral Gland
Duct Dilatation
Overall rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | – | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.237 | – | – | – | – | p = 0.237
Average severity | – | – | – | – | – | 4.0
Chronic Active Inflammation
Overall rate | 2/10 (20.0%) | – | – | – | – | 2/10 (20.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.709N | – | – | – | – | p = 0.709N
Average severity | 2.5 | – | – | – | – | 2.0
Infiltration Cellular
Overall rate | 3/10 (30.0%) | – | – | – | – | 3/10 (30.0%)
Terminal rate | 3/10 (30.0%) | – | – | – | – | 3/10 (30.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.686N | – | – | – | – | p = 0.686N
Average severity | 2.0 | – | – | – | – | 1.3
Uterus
Lumen Dilatation
Overall rate | 3/10 (30.0%) | – | – | – | – | 1/10 (10.0%)
Terminal rate | 3/10 (30.0%) | – | – | – | – | 1/10 (10.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.291N | – | – | – | – | p = 0.291N
Average severity | 3.0 | – | – | – | – | 4.0
Mesenteric Lymph Node
Hyperplasia
Overall rate | 3/10 (30.0%) | – | – | – | – | 1/10 (10.0%)
Terminal rate | 3/10 (30.0%) | – | – | – | – | 1/10 (10.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.291N | – | – | – | – | p = 0.291N
Average severity | 1.7 | – | – | – | – | 2.0
Infiltration Cellular
Overall rate | 9/10 (90.0%) | – | – | – | – | 10/10 (100.0%)
Terminal rate | 9/10 (90.0%) | – | – | – | – | 10/10 (100.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500 | – | – | – | – | p = 0.500
Average severity | 1.8 | – | – | – | – | 3.0
Harderian Gland
Infiltration Cellular
Overall rate | 3/10 (30.0%) | – | – | – | – | 0/10 (0.0%)
Terminal rate | 3/10 (30.0%) | – | – | – | – | 0/10 (0.0%)
First incidence (days) | 90 (T) | – | – | – | – | –
CAFÉ p value | p = 0.105N | – | – | – | – | p = 0.105N
Average severity | 1.3 | – | – | – | – | –
Kidney
Mineralization
Overall rate | 10/10 (100.0%) | – | – | – | – | 10/10 (100.0%)
Terminal rate | 10/10 (100.0%) | – | – | – | – | 10/10 (100.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | – | – | – | – | – | –
Average severity | 3.0 | – | – | – | – | 3.4
Cyst
Overall rate | 2/10 (20.0%) | – | – | – | – | 1/10 (10.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | – | 1/10 (10.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500N | – | – | – | – | p = 0.500N
Average severity | 3.5 | – | – | – | – | 4.0
Nephropathy
Overall rate | 2/10 (20.0%) | – | – | – | – | 10/10 (100.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | – | 10/10 (100.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p ≤ 0.001 | – | – | – | – | p ≤ 0.001
Average severity | 1.0 | – | – | – | – | 1.2

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Indicates no data were collected.

^c^ Observed incidence at terminal sacrifice.

^d^ Time to first lesion in days. T indicates terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with dose. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

Table A-5 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths | 0 | 0 | 0 | 0 | 0 | 0
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10)^a^ | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | 1 (10%) | –^b^ | – | – | – | 0
Tension lipidosis | 1 (10%) | – | – | – | – | 2 (20%)
Vacuolization cytoplasmic | 6 (60%) | – | – | – | – | 2 (20%)
Stomach, Forestomach | (10) | (0) | (0) | (0) | (0) | (10)
Epithelium, hyperplasia | 1 (10%) | – | – | – | – | 0
Cardiovascular System
None
Endocrine System
Adrenal Cortex | (10) | (0) | (0) | (0) | (0) | (10)
Subcapsular, hyperplasia | 1 (10%) | – | – | – | – | 1 (10%)
General Body System
None
Genital System
Preputial Gland | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 0 | – | – | – | – | 1 (10%)
Hematopoietic System
Lymph Node, Mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Hyperplasia, lymphoid | 3 (30%) | – | – | – | – | 2 (20%)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic cell proliferation | 0 | – | – | – | – | 2 (20%)
Hyperplasia, lymphoid | 0 | – | – | – | – | 2 (20%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
Urinary Bladder | (10) | (0) | (0) | (0) | (0) | (10)
Lumen, dilatation | 0 | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-6 Statistical Analysis of Nonneoplastic Lesions in Male Mice in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Liver
Vacuolization Cytoplasmic
Overall rate^a^ | 6/10 (60.0%) | –^b^ | – | – | – | 2/10 (20.0%)
Terminal rate^c^ | 6/10 (60.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days)^d^ | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value^e^ | p = 0.085N | – | – | – | – | p = 0.085N
Average severity^f^ | 1.2 | – | – | – | – | 1.0
Tension Lipidosis
Overall rate | 1/10 (10.0%) | – | – | – | – | 2/10 (20.0%)
Terminal rate | 1/10 (10.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500 | – | – | – | – | p = 0.500
Average severity | 2.0 | – | – | – | – | 1.0
Spleen
Hematopoietic Cell Proliferation
Overall rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | – | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.237 | – | – | – | – | p = 0.237
Average severity | – | – | – | – | – | 2.0
Lymphoid Hyperplasia
Overall rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | – | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.237 | – | – | – | – | p = 0.237
Average severity | – | – | – | – | – | 2.0
Mesenteric Lymph Node
Lymphoid Hyperplasia
Overall rate | 3/10 (30.0%) | – | – | – | – | 2/10 (20.0%)
Terminal rate | 3/10 (30.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.500N | – | – | – | – | p = 0.500N
Average severity | 1.7 | – | – | – | – | 1.5

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Indicates no data were collected.

^c^ Observed incidence at terminal sacrifice.

^d^ Time to first lesion in days. T indicates terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with dose. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

Table A-7 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Disposition Summary
Animals Initially in Study | 10 | 10 | 10 | 10 | 10 | 10
Early Deaths
Accidentally killed | 0 | 0 | 1 | 0 | 0 | 0
Survivors
Terminal sacrifice | 10 | 10 | 9 | 10 | 10 | 10
Alimentary System
Liver | (10)^a^ | (0) | (1) | (0) | (0) | (10)
Inflammation, chronic active | 0 | –^b^ | 0 | – | – | 2 (20%)
Tension lipidosis | 1 (10%) | – | 0 | – | – | 0
Vacuolization cytoplasmic | 4 (40%) | – | 1 (100%) | – | – | 0
Cardiovascular System
None
Endocrine System
Adrenal Cortex | (10) | (0) | (1) | (0) | (0) | (10)
Subcapsular, hyperplasia | 10 (100%) | – | 1 (100%) | – | – | 10 (100%)
Thyroid Gland | (10) | (0) | (1) | (0) | (0) | (10)
Ectopic thymus | 1 (10%) | – | 0 | – | – | 0
General Body System
None
Genital System
Uterus | (10) | (0) | (1) | (0) | (0) | (10)
Endometrium, hyperplasia | 0 | – | 0 | – | – | 1 (10%)
Hematopoietic System
Bone Marrow | (10) | (0) | (1) | (0) | (0) | (10)
Hyperplasia | 1 (10%) | – | 0 | – | – | 0
Lymph Node, Mesenteric | (10) | (0) | (1) | (0) | (0) | (10)
Hyperplasia, lymphoid | 0 | – | 0 | – | – | 1 (10%)
Spleen | (10) | (0) | (1) | (0) | (0) | (10)
Hematopoietic cell proliferation | 2 (20%) | – | 0 | – | – | 2 (20%)
Hyperplasia, lymphoid | 4 (40%) | – | 0 | – | – | 0
Thymus | (10) | (0) | (1) | (0) | (0) | (10)
Hyperplasia, lymphoid | 0 | – | 0 | – | – | 2 (20%)
Necrosis | 1 (10%) | – | 0 | – | – | 0
Integumentary System
None
Musculoskeletal System
Bone | (0) | (0) | (1) | (0) | (0) | (0)
Cranium, fracture | – | – | 1 (100%) | – | – | –
Cranium, hemorrhage | – | – | 1 (100%) | – | – | –
Nervous System
Brain, Brain Stem | (10) | (0) | (1) | (0) | (0) | (10)
Hemorrhage | 0 | – | 1 (100%) | – | – | 0
Brain, Cerebellum | (10) | (0) | (1) | (0) | (0) | (10)
Hemorrhage | 0 | – | 1 (100%) | – | – | 0
Brain, Cerebrum | (10) | (0) | (1) | (0) | (0) | (10)
Hemorrhage | 0 | – | 1 (100%) | – | – | 0
Respiratory System
Lung | (10) | (0) | (1) | (0) | (0) | (10)
Hemorrhage | 0 | – | 1 (100%) | – | – | 0
Nose | (10) | (0) | (1) | (0) | (0) | (10)
Hemorrhage | 0 | – | 1 (100%) | – | – | 0
Special Senses System
None
Urinary System
None

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Indicates no data were collected.

Table A-8 Statistical Analysis of Nonneoplastic Lesions in Female Mice in the Three-month Feed Study of (+)-Usnic Acid

| 0 ppm | 15 ppm | 30 ppm | 60 ppm | 180 ppm | 360 ppm
Liver
Vacuolization Cytoplasmic
Overall rate^a^ | 4/10 (40.0%) | –^b^ | 1/1 (100.0%) | – | – | 0/10 (0.0%)
Terminal rate^c^ | 4/10 (40.0%) | – | – | – | – | 0/10 (0.0%)
First incidence (days)^d^ | 90 (T) | – | 17 | – | – | –
CAFÉ p value^e^ | p = 0.023N | – | p = 0.206 | – | – | p = 0.043N
Average severity^f^ | 1.3 | – | 2 | – | – | –
Inflammation
Overall rate | 0/10 (0.0%) | – | 0/1 (0.0%) | – | – | 2/10 (20.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | – | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.214 | – | – | – | – | p = 0.237
Average severity | – | – | – | – | – | 1.0
Adrenal Cortex
Subcapsular Hyperplasia
Overall rate | 10/10 (100.0%) | – | 1/1 (100.0%) | – | – | 10/10 (100.0%)
Terminal rate | 10/10 (100.0%) | – | – | – | – | 10/10 (100.0%)
First incidence (days) | 90 (T) | – | 17 | – | – | 90 (T)
CAFÉ p value | – | – | – | – | – | –
Average severity | 1.0 | – | 1 | – | – | 1.1
Spleen
Hematopoietic Cell Proliferation
Overall rate | 2/10 (20.0%) | – | 0/1 (0.0%) | – | – | 2/10 (20.0%)
Terminal rate | 2/10 (20.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.669 | – | – | – | – | p = 0.709N
Average severity | 2.0 | – | – | – | – | 2.0
Lymphoid Hyperplasia
Overall rate | 4/10 (40.0%) | – | 0/1 (0.0%) | – | – | 0/10 (0.0%)
Terminal rate | 4/10 (40.0%) | – | – | – | – | 0/10 (0.0%)
First incidence (days) | 90 (T) | – | – | – | – | –
CAFÉ p value | p = 0.035N | – | – | – | – | p = 0.043N
Average severity | 2.0 | – | – | – | – | –
Thymus
Lymphoid Hyperplasia
Overall rate | 0/10 (0.0%) | – | 0/1 (0.0%) | – | – | 2/10 (20.0%)
Terminal rate | 0/10 (0.0%) | – | – | – | – | 2/10 (20.0%)
First incidence (days) | 90 (T) | – | – | – | – | 90 (T)
CAFÉ p value | p = 0.224 | – | – | – | – | p = 0.237
Average severity | – | – | – | – | – | 2.0

^a^ Number of nonneoplastic lesion-bearing animals over number of animals examined.

^b^ Indicates no data were collected.

^c^ Observed incidence at terminal sacrifice.

^d^ Time to first lesion in days. T indicates terminal sacrifice.

^e^ The exact Cochran-Armitage trend test was used to test for a trend in nonneoplastic incidence with dose. Fisher’s exact test was used to compare incidences between exposed groups and the control group. Tests for trend and comparisons of exposed groups to control were performed as one-sided tests. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.