# Overview

Ionic liquids (ILs) are synthetic solvents composed of organic cations and organic or inorganic anions. Because the cations can have numerous alkyl chain substitutions, the number of potential IL combinations is estimated to exceed 10 trillion.^1^ Chemicals from this class have replaced volatile organic compounds (VOCs) in the pharmaceutical, chemical, and energy industries, among others, because they are potentially less toxic and more environmentally friendly than VOCs.^2,3^

Although research has shown that some ILs are ecotoxic,^4^ few studies characterize the toxicity of these compounds in humans. In a recent metanalysis of ionic liquid literature and toxicology, in vivo mammalian toxicity studies constituted only 8% of all tests conducted with these compounds.^5^ Four ionic liquids—1-ethyl-3-methylimidazolium chloride (Emim-Cl), 1-butyl-3-methylimidazolium chloride (Bmim-Cl), 1-butyl-1-methylpyrrolidinium chloride (Bmpy-Cl), and n-butylpyridinium chloride (NBuPy-Cl)—were nominated to the National Toxicology Program (NTP) for testing due to widespread interest in using them as solvent alternatives to VOCs. These four compounds were recommended for toxicity testing because, at the time of nomination, they represented the three most common cation classes (i.e., imidazolium, pyridinium, and pyrrolidinium) used in various industrial applications. In addition to investigating whether one cation is more toxic than another, two imidazolium compounds with different chain lengths (2-carbon Emim-Cl and 4-carbon Bmim-Cl) were nominated to determine whether alkyl chain length can contribute significantly to toxicity.

The structure of an IL determines its stability, bioavailability, and potential toxicity. Thus, NTP aimed to determine the general and relative toxicity of members of this chemical class and to test the hypothesis that specific structural variations (e.g., alkyl chain length) alter relative toxicity. Because of the potential for human exposure, NTP designed a series of studies to investigate effects of these four ILs on skin sensitization, genotoxicity, and short-term and subchronic toxicity and to learn more about their absorption, distribution, metabolism, and excretion. This toxicity report presents results from the 2-week (short-term) and 3-month (subchronic) studies of adult male and female rats and mice following IL exposure via drinking water.