# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  R.A. Dee, Ph.D., Co-Study Scientist
  K.R. Ryan, Ph.D., Co-Study Scientist
  S.A. Elmore, D.V.M., M.S., Study Pathologist
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  R.P. Frawley, M.S.
  D.R. Germolec, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  E. Mutlu, Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted 3-month studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  B.R. Sparrow, Ph.D., Principal Investigator
  T.P. Arndt, Ph.D.
  M.A. Buccellato, D.V.M., Ph.D.
  P.S. Coder, Ph.D.
  C.A. Granville, Ph.D.
  S.J. Harbo, D.V.M.
  K.A.B. Knostman, D.V.M., Ph.D.
  E. Mylchreest, Ph.D.
  K.M. Patton, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
  A.M. Zmarowski, Ph.D.
- Conducted prestart chemistry activities and dose formulations
  B.L. Burback, Ph.D.
  P.S. Clemons, Ph.D.
  D.A. Contos, M.S.
  S.W. Graves, B.S.
  J.S. Richey, M.S.
  N.L. South, B.S.
- BioReliance Corporation, Rockville, Maryland, USA
  Conducted 2-week studies
  M.L. Wenk, Ph.D., Principal Investigator
  R.H. Elbekai, Ph.D.
  M. Paranjpe, D.V.M., Ph.D.
  S.A. Shah, Ph.D.
- MRIGlobal, Kansas City, Missouri, USA
  Conducted preliminary chemistry activities
  J.W. Algaier, Ph.D., Principal Investigator
  A.P. Clark, B.S.E., Co-Principal Investigator
  K.L. Aillon, Ph.D.
  B. Astroff, Ph.D.
  J. Cookinham, B.S.
  A. Kazerooni, M.S.
  A.J. Mainey, B.S.
  D. Messer, Ph.D.
  B. O’Brien, M.S.
  M. Roth, B.S.
  K.E. Schnare, B.S.
  L. Siemann, B.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  K.Y. Cimon, D.V.M.
- Coordinated NTP Pathology Working Group on 3-month mice (July 30, 2019)
  K.Y. Cimon, D.V.M.
- ICF, Fairfax, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  K.E. Setty, Ph.D.