# References

1 Baker GA, Baker SN, Pandey S, Bright FV. An analytical view of ionic liquids. Analyst. 2005; 130(6):800–808. 10.1039/b500865b 15912225
2 Rogers RD, Seddon KR. Chemistry. Ionic liquids—solvents of the future? Science. 2003; 302(5646):792–793. 10.1126/science.1090313 14593156
3 Miskiewicz A, Ceranowicz P, Szymczak M, Bartuś K, Kowalczyk P. The use of liquids ionic fluids as pharmaceutically active substances helpful in combating nosocomial infections induced by Klebsiella Pneumoniae New Delhi strain, Acinetobacter Baumannii and Enterococcus species. Int J Mol Sci. 2018; 19(9). 10.3390/ijms19092779 30223584
4 Pham TP, Cho C-W, Yun Y-S. Environmental fate and toxicity of ionic liquids: A review. Water Res. 2010; 44(2):352–372. 10.1016/j.watres.2009.09.030 19854462
5 Heckenbach ME, Romero FN, Green MD, Halden RU. Meta-analysis of ionic liquid literature and toxicology. Chemosphere. 2016; 150:266–274. 10.1016/j.chemosphere.2016.02.029 26907595
6 Endres F, Zein El Abedin S. Air and water stable ionic liquids in physical chemistry. Phys Chem Chem Phys. 2006; 8(18):2101–2116. 10.1039/b600519p 16751868
7 Castner EW Jr, Margulis CJ, Maroncelli M, Wishart JF. Ionic liquids: Structure and photochemical reactions. Annu Rev Phys Chem. 2011; 62:85–105. 10.1146/annurev-physchem-032210-103421 21091193
8 Cvjetko Bubalo M, Radošević K, Redovniković IR, Halambek J, Srček VG. A brief overview of the potential environmental hazards of ionic liquids. Ecotoxicol Environ Saf. 2014;99:1–12. 10.1016/j.ecoenv.2013.10.019 24210364
9 Freemantle M. Designer solvents-ionic liquids may boost clean technology development. Chem Eng News. 1998; 76(13):32–37. 10.1021/cen-v076n013.p032
10 Freemantle M. Eyes on ionic liquids. Chem Eng News. 2000; 78(20):37–50. 10.1021/cen-v078n020.p037
11 Plechkova NV, Seddon KR. Applications of ionic liquids in the chemical industry. Chem Soc Rev. 2008; 37(1):123–150. 10.1039/B006677J 18197338
12 Holbrey JD, Seddon KR. Ionic liquids. Clean Products and Processes. 1999; 1(4):223–236. 10.1007/s100980050036
13 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: 1-Ethyl-3-methylimidazolium chloride 65039-09-0 | DTXSID1041180. https://comptox.epa.gov/dashboard/dsstoxdb/results?search=DTXSID1041180#properties
14 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: 1-Butyl-3-methylimidazolium chloride 79917-90-1 | DTXSID6031461. https://comptox.epa.gov/dashboard/dsstoxdb/results?search=DTXSID6031461#properties
15 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: 1-Butyl-1-methylpyrrolidinium chloride 479500-35-1 | DTXSID1031460. https://comptox.epa.gov/dashboard/dsstoxdb/results?search=479500-35-1#properties
16 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: N-Butylpyridinium chloride 1124-64-7 | DTXSID1031462. https://comptox.epa.gov/dashboard/dsstoxdb/results?search=1124-64-7#properties
17 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard. https://comptox.epa.gov/dashboard
18 National Center for Biotechnology Information (NCBI). PubChem. Bethesda, MD: National Library of Medicine. https://pubchem.ncbi.nlm.nih.gov/
19 Wilkes JS. A short history of ionic liquids—from molten salts to neoteric solvents. Green Chem. 2002; 4(2):73–80. 10.1039/b110838g
20 Angell CA, Ansari Y, Zhao Z. Ionic liquids: Past, present and future. Faraday Discuss. 2012;154:9–27. 10.1039/C1FD00112D 22455011
21 Welton T. Ionic liquids: A brief history. Biophys Rev. 2018; 10(3):691–706. 10.1007/s12551-018-0419-2 29700779
22 Grand View Research. Ionic liquids market size, share & trends analysis report by application (solvents & catalysts, extractions & separations, bio-refineries, energy storage), by region, and segment forecasts, 2018 - 2025. 2016. https://www.grandviewresearch.com/industry-analysis/ionic-liquids-market
23 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 2734160, 1-Ethyl-3-methylimidazolium chloride: 6. Chemical Vendors. Bethesda, MD: National Library of Medicine; 2020. https://pubchem.ncbi.nlm.nih.gov/compound/2734160#section=Chemical-Vendors [12/14/2020]
24 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 2734161, 1-Butyl-3-methylimidazolium chloride: 5. Chemical Vendors. Bethesda, MD: National Library of Medicine; 2020. https://pubchem.ncbi.nlm.nih.gov/compound/2734161#section=Chemical-Vendors [12/14/2020]
25 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 11769095, 1-Butyl-1-methylpyrrolidinium chloride: 5. Chemical Vendors. Bethesda, MD: National Library of Medicine; 2020. https://pubchem.ncbi.nlm.nih.gov/compound/11769095#section=Chemical-Vendors [12/14/2020]
26 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 2734171, n-Butylpyridinium chloride: 6. Chemical Vendors. Bethesda, MD: National Library of Medicine; 2020. https://pubchem.ncbi.nlm.nih.gov/compound/2734171#section=Chemical-Vendors [12/14/2020]
27 Goindi S, Arora P, Kumar N, Puri A. Development of novel ionic liquid-based microemulsion formulation for dermal delivery of 5-Fluorouracil. AAPS PharmSciTech. 2014; 15(4):810–821. 10.1208/s12249-014-0103-1 24668136
28 Wang C, Zhu J, Zhang D, Yang Y, Zheng L, Qu Y, Yang X, Cui X. Ionic liquid - microemulsions assisting in the transdermal delivery of Dencichine: Preparation, in-vitro and in-vivo evaluations, and investigation of the permeation mechanism. Int J Pharm. 2018; 535(1-2):120–131. 10.1016/j.ijpharm.2017.10.024 29104058
29 Dobler D, Schmidts T, Zinecker C, Schlupp P, Schäfer J, Runkel F. Hydrophilic ionic liquids as ingredients of gel-based dermal formulations. AAPS PharmSciTech. 2016; 17(4):923–931. 10.1208/s12249-015-0421-y 27435197
30 Wang P, Yu H, Zhan S, Wang S. Catalytic hydrolysis of lignocellulosic biomass into 5-hydroxymethylfurfural in ionic liquid. Bioresour Technol. 2011; 102(5):4179–4183. 10.1016/j.biortech.2010.12.073 21232942
31 Nordwald EM, Kaar JL. Mediating electrostatic binding of 1-butyl-3-methylimidazolium chloride to enzyme surfaces improves conformational stability. J Phys Chem B. 2013; 117(30):8977–8986. 10.1021/jp404760w 23822219
32 Tavares APM, Pinho B, Rodriguez O, Macedo EA. Biocatalysis in ionic liquid: Degradation of phenol by laccase. Procedia Eng. 2012; 42:226–230. 10.1016/j.proeng.2012.07.413
33 Ventura SP, Neves CM, Freire MG, Marrucho IM, Oliveira J, Coutinho JA. Evaluation of anion influence on the formation and extraction capacity of ionic-liquid-based aqueous biphasic systems. J Phys Chem B. 2009; 113(27):9304–9310. 10.1021/jp903286d 19518115
34 Du Z, Yu YL, Wang JH. Extraction of proteins from biological fluids by use of an ionic liquid/aqueous two-phase system. Chemistry. 2007; 13(7):2130–2137. 10.1002/chem.200601234 17136782
35 National Toxicology Program (NTP). Ionic liquids: 1-Butyl-3-methylimidazolium chloride (CAS No. 79917-90-1), 1-butyl-1-methylpyrrolidinium chloride (CAS No. 479500-35-1), n-butylpyridinium chloride (CAS No. 1124-64-7). Review of toxicological literature. Research Triangle Park, NC: Prepared by: Integrated Laboratory Systems, Inc.; 2004. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/ionic_liquids_508.pdf
36 Wang C, Wang Y, Lu Y, He H, Huo F, Dong K, Wei N, Zhang S. Height-driven structure and thermodynamic properties of confined ionic liquids inside carbon nanochannels from molecular dynamics study. Phys Chem Chem Phys. 2019; 21(24):12767–12776. 10.1039/C9CP00732F 31020276
37 Chen K, Xu W, Ding Y, Xue P, Sheng P, Qiao H, He J. Hemp-based all-cellulose composites through ionic liquid promoted controllable dissolution and structural control. Carbohydr Polym. 2020; 235:116027. 10.1016/j.carbpol.2020.116027 32122518
38 Hwang JH, Park H, Choi DW, Nam KT, Lim KM. Investigation of dermal toxicity of ionic liquids in monolayer-cultured skin cells and 3D reconstructed human skin models. Toxicol In Vitro. 2018; 46:194–202. 10.1016/j.tiv.2017.09.025 28958837
39 Kohli R. Applications of ionic liquids in removal of surface contaminants. In: Kohli R, Mittal KL, editors. Developments in Surface Contamination and Cleaning: Applications of Cleaning Techniques. Elsevier; 2019. p. 619–680. 10.1016/B978-0-12-815577-6.00016-5
40 Berton P, Bica K, Rogers RD. Ionic liquids for consumer products: Dissolution, characterization, and controlled release of fragrance compositions. Fluid Phase Equilib. 2017; 450:51–56. 10.1016/j.fluid.2017.07.011
41 Anthony JL, Maginn EJ, Brennecke JF. Solution thermodynamics of imidazolium-based ionic liquids and water. J Phys Chem B. 2001; 105(44):10942–10949. 10.1021/jp0112368
42 McFarlane J, Ridenour WB, Luo H, Hunt RD, DePaoli DW, Ren RX. Room temperature ionic liquids for separating organics from produced water. Sep Sci Technol. 2005; 40(6):1245–1265. 10.1081/SS-200052807
43 Cheng Y, Wright SH, Hooth MJ, Sipes IG. Characterization of the disposition and toxicokinetics of N-butylpyridinium chloride in male F-344 rats and female B6C3F1 mice and its transport by organic cation transporter 2. Drug Metab Dispos. 2009; 37(4):909–916. 10.1124/dmd.108.022681 19171679
44 Sipes IG, Knudsen GA, Kuester RK. The effects of dose and route on the toxicokinetics and disposition of 1-butyl-3-methylimidazolium chloride in male F-344 rats and female B6C3F1 mice. Drug Metab Dispos. 2008; 36(2):284–293. 10.1124/dmd.107.018515 17967929
45 Knudsen GA, Cheng Y, Kuester RK, Hooth MJ, Sipes IG. Effects of dose and route on the disposition and kinetics of 1-butyl-1-methylpyrrolidinium chloride in male F-344 rats. Drug Metab Dispos. 2009; 37(11):2171–2177. 10.1124/dmd.109.029082 19704025
46 Landry TD, Brooks K, Poche D, Woolhiser M. Acute toxicity profile of 1-butyl-3-methylimidazolium chloride. Bull Environ Contam Toxicol. 2005; 74(3):559–565. 10.1007/s00128-005-0620-4 15903191
47 Jastorff B, Störmann R, Ranke J, Mölter K, Stock F, Oberheitmann B, Hoffmann W, Hoffmann J, Nüchter M, Ondruschka B, et al. How hazardous are ionic liquids? Structure–activity relationships and biological testing as important elements for sustainability evaluation. Green Chem. 2003; 5(2):136–142. 10.1039/b211971d
48 Cheng Y, Martinez-Guerrero LJ, Wright SH, Kuester RK, Hooth MJ, Sipes IG. Characterization of the inhibitory effects of N-butylpyridinium chloride and structurally related ionic liquids on organic cation transporters 1/2 and human toxic extrusion transporters 1/2-k in vitro and in vivo. Drug Metab Dispos. 2011; 39(9):1755–1761. 10.1124/dmd.110.035865 21646436
49 Chen Y, Zhang S, Sorani M, Giacomini KM. Transport of paraquat by human organic cation transporters and multidrug and toxic compound extrusion family. J Pharmacol Exp Ther. 2007; 322(2):695–700. 10.1124/jpet.107.123554 17495125
50 Koepsell H, Lips K, Volk C. Polyspecific organic cation transporters: Structure, function, physiological roles, and biopharmaceutical implications. Pharm Res. 2007; 24(7):1227–1251. 10.1007/s11095-007-9254-z 17473959
51 Koepsell H. Organic cation transporters in intestine, kidney, liver, and brain. Annu Rev Physiol. 1998; 60:243–266. 10.1146/annurev.physiol.60.1.243 9558463
52 Kim MK, Han L, Choi MK, Han Y-H, Kim D-D, Chung S-J, Shim C-K. Dose dependency in the oral bioavailability of an organic cation model, tributylmethyl ammonium (TBuMA), in rats: Association with the saturation of efflux by the P-gp system on the apical membrane of the intestinal epithelium. J Pharm Sci. 2005; 94(12):2644–2655. 10.1002/jps.20456 16258993
53 Suhre WM, Ekins S, Chang C, Swaan PW, Wright SH. Molecular determinants of substrate/inhibitor binding to the human and rabbit renal organic cation transporters hOCT2 and rbOCT2. Mol Pharmacol. 2005; 67(4):1067–1077. 10.1124/mol.104.004713 15630081
54 Choi MK, Jin QR, Jin HE, Shim CK, Cho DY, Shin JG, Song IS. Effects of tetraalkylammonium compounds with different affinities for organic cation transporters on the pharmacokinetics of metformin. Biopharm Drug Dispos. 2007; 28(9):501–510. 10.1002/bdd.576 17876861
55 Liu T, Guo Y, Wang J, Wang J, Zhu L, Zhang J, Zhang C. Assessing toxic effects of [Omim]Cl and [Omim]BF4 in zebrafish adults using a biomarker approach. Environ Sci Pollut Res Int. 2016; 23(8):7360–7368. 10.1007/s11356-015-5887-3 26686854
56 Fatemi MH, Izadiyan P. Cytotoxicity estimation of ionic liquids based on their effective structural features. Chemosphere. 2011; 84(5):553–563. 10.1016/j.chemosphere.2011.04.021 21549407
57 Gomez-Herrero E, Tobajas M, Polo A, Rodriguez JJ, Mohedano AF. Toxicity and inhibition assessment of ionic liquids by activated sludge. Ecotoxicol Environ Saf. 2020; 187:109836. 10.1016/j.ecoenv.2019.109836 31675504
58 Larson JH, Frost PC, Lamberti GA. Variable toxicity of ionic liquid–forming chemicals to Lemna minor and the influence of dissolved organic matter. Environ Toxicol Chem. 2008; 27(3):676–681. 10.1897/06-540.1 17967067
59 Ranke J, Müller A, Bottin-Weber U, Stock F, Stolte S, Arning J, Störmann R, Jastorff B. Lipophilicity parameters for ionic liquid cations and their correlation to in vitro cytotoxicity. Ecotoxicol Environ Saf. 2007; 67(3):430–438. 10.1016/j.ecoenv.2006.08.008 17034854
60 Tsarpali V, Belavgeni A, Dailianis S. Investigation of toxic effects of imidazolium ionic liquids, [bmim][BF4] and [omim][BF4], on marine mussel Mytilus galloprovincialis with or without the presence of conventional solvents, such as acetone. Aquat Toxicol. 2015; 164:72–80. 10.1016/j.aquatox.2015.04.021 25935102
61 Mester P, Wagner M, Rossmanith P. Antimicrobial effects of short chained imidazolium-based ionic liquids—Influence of anion chaotropicity. Ecotoxicol Environ Saf. 2015; 111:96–101. 10.1016/j.ecoenv.2014.08.032 25450920
62 Mendonça CMN, Balogh DT, Barbosa SC, Sintra TE, Ventura SPM, Martins LFG, Morgado P, Filipe EJM, Coutinho JAP, Oliveira ON, et al. Understanding the interactions of imidazolium-based ionic liquids with cell membrane models. Phys Chem Chem Phys. 2018; 20(47):29764–29777. 10.1039/C8CP05035J 30462106
63 Kusumahastuti DKA, Sihtmäe M, Kapitanov IV, Karpichev Y, Gathergood N, Kahru A. Toxicity profiling of 24 l-phenylalanine derived ionic liquids based on pyridinium, imidazolium and cholinium cations and varying alkyl chains using rapid screening Vibrio fischeri bioassay. Ecotoxicol Environ Saf. 2019; 172:556–565. 10.1016/j.ecoenv.2018.12.076 30776578
64 Li X-Y, Jing C-Q, Zang X-Y, Yang S, Wang J-J. Toxic cytological alteration and mitochondrial dysfunction in PC12 cells induced by 1-octyl-3-methylimidazolium chloride. Toxicol In Vitro. 2012; 26(7):1087–1092. 10.1016/j.tiv.2012.07.006 22835898
65 Wang P, Wan R, Huo W, Dong H, Chang Z, Xia X. Cytotoxicity, genotoxicity, oxidative stress, and apoptosis in HepG2 cells induced by the imidazole ionic liquid 1-dodecyl-3-methylimidazolium chloride. Environ Toxicol. 2020; 35(6):665–672. 10.1002/tox.22901 31916396
66 Lim GS, Zidar J, Cheong DW, Jaenicke S, Klähn M. Impact of ionic liquids in aqueous solution on bacterial plasma membranes studied with molecular dynamics simulations. J Phys Chem B. 2014; 118(35):10444–10459. 10.1021/jp5060952 25153890
67 Losada-Pérez P, Khorshid M, Renner FU. Interactions of aqueous imidazolium-based ionic liquid mixtures with solid-supported phospholipid vesicles. PLoS One. 2016; 11(9):e0163518. 10.1371/journal.pone.0163518 27684947
68 Bailey MM, Jernigan PL, Henson MB, Sturdivant J, Rasco JF, Lovich AN, Lockhard JE, Hough WL, Di Bona KR, Beaird J, et al. A comparison of the effects of prenatal exposure of CD-1 mice to three imidazolium-based ionic liquids. Birth Defects Res B Dev Reprod Toxicol. 2010; 89(3):233–238. 10.1002/bdrb.20251 20540104
69 Frawley RP, Germolec DR, Johnson VJ, Gulledge T, Manheng W, White K Jr, Shockley KR, Harris SF, Hooth M, Ryan K. Evaluation of skin sensitization induced by four ionic liquids. J Appl Toxicol. 2022; 42(3):392–408. 10.1002/jat.4224 34453447
70 Organisation for Economic Co-operation and Development (OECD). Test no 442C: In chemico skin sensitisation: Direct peptide reactivity assay (DPRA). 2015.
71 Organisation for Economic Co-operation and Development (OECD). Test no 442D: In vitro skin sensitisation assays addressing the AOP key event of keratinocyte activation. 2018. 10.1787/9789264229822-en
72 Organisation for Economic Co-operation and development (OECD). Test no. 442E: In vitro skin sensitisation assays addressing the key event on activation of dendritic cells on the adverse outcome pathway for skin sensitisation. 2018. https://www.oecd-ilibrary.org/content/publication/9789264264359-en
73 Emter R, Ellis G, Natsch A. Performance of a novel keratinocyte-based reporter cell line to screen skin sensitizers in vitro. Toxicol Appl Pharmacol. 2010; 245(3):281–290. 10.1016/j.taap.2010.03.009 20307559
74 Mitachi T, Mezaki M, Yamashita K, Itagaki H. Acidic conditions induce the suppression of CD86 and CD54 expression in THP-1 cells. J Toxicol Sci. 2018; 43(5):299–309. 10.2131/jts.43.299 29743441
75 Hernández-Fernández FJ, Bayo J, Pérez de los Ríos A, Vicente MA, Bernal FJ, Quesada-Medina J. Discovering less toxic ionic liquids by using the Microtox® toxicity test. Ecotoxicol Environ Saf. 2015; 116:29–33. 10.1016/j.ecoenv.2015.02.034 25748519
76 National Center for Biotechnology Information (NCBI). PubChem Compound LCSS for CID 2734161, 1-Butyl-3-methylimidazolium chloride: 1. GHS Classification. Bethesda, MD: National Library of Medicine; 2019. https://pubchem.ncbi.nlm.nih.gov/compound/2734161#datasheet=LCSS&section=GHS-Classification
77 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
78 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
79 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
80 Armitage P. Statistical Methods in Medical Research. Oxford: Blackwell; 1971.
81 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
82 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
83 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
84 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
85 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
86 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
87 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
88 Dixon W, Massey F. Introduction to Statistical Analysis. New York, NY: McGraw Hill Book Company Inc; 1957. 10.2307/2332898
89 Kalbfleisch JD, Lawless JF. The analysis of panel data under a Markov assumption. J Am Stat Assoc. 1985; 80(392):863–871. 10.1080/01621459.1985.10478195
90 Code of Federal Regulations (CFR). 21(Part 58).
91 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
92 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67:233–241. 7021938
93 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
94 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
95 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
96 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden H. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16(S18):1–14. 10.1002/em.2850160502 2091921
97 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
98 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
99 Shelby MD, Witt KL. Comparison results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25:302–313. 10.1002/em.2850250407 7607185
100 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
101 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
102 National Toxicology Program (NTP). Pathology tables, survival and growth curves from NTP 1-butyl-3-methylimidazolium chloride, 1-butyl-1-methylpyrrolidinium chloride, 1-ethyl-3-methylimidazolium chloride, n-butylpyridinium chloride, and genetic toxicology studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. 10.22427/NTP-DATA-TOX-103
103 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614. 10.1177/0192623312466452 23475558
104 Frazier KS, Seely JC, Hard GC, Betton G, Burnett R, Nakatsuji S, Nishikawa A, Durchfeld-Meyer B, Bube A. Proliferative and nonproliferative lesions of the rat and mouse urinary system. Toxicol Pathol. 2012; 40(4 Suppl):14s–86s. 10.1177/0192623312438736 22637735
105 Ormos J, Sztriha L, Bóti ZS, Kuthy E. Electron microscopic and cytochemical study of the vacuoles of regenerating renal tubular cells. Br J Exp Pathol. 1975; 56(5):477–483. 1212429
106 Gannon A-L, O’Hara L, Mason JI, Jørgensen A, Frederiksen H, Milne L, Smith S, Mitchell RT, Smith LB. Androgen receptor signalling in the male adrenal facilitates X-zone regression, cell turnover and protects against adrenal degeneration during ageing. Sci Rep. 2019; 9(1):10457. 10.1038/s41598-019-46049-3 31320667
107 Davey P. Ionic liquids in consumer products: The possible uses for ionic liquids in fragrances and household products. 2008. https://media.allured.com/documents/PF_33_04_034_02.pdf
108 Agatemor C, Ibsen KN, Tanner EEL, Mitragotri S. Ionic liquids for addressing unmet needs in healthcare. Bioeng Transl Med. 2018; 3(1):7–25. 10.1002/btm2.10083 29376130
109 Oskarsson A, Wright MC. Ionic liquids: New emerging pollutants, aimilarities with perfluorinated alkyl substances (PFASs). Environ Sci Technol. 2019; 53(18):10539–10541. 10.1021/acs.est.9b04778 31442027
110 Romero A, Santos A, Tojo J, Rodríguez A. Toxicity and biodegradability of imidazolium ionic liquids. J Hazard Mater. 2008; 151(1):268–273. 10.1016/j.jhazmat.2007.10.079 18063302
111 Claassen V. Food and water intake. In: Techniques in the Behavioral and Neural Sciences Neglected Factors in Pharmacology and Neuroscience Research: Biophamaceutics, Animal Characteristics Maintenance, Testing Conditions. Elsevier; 1994. p. 267–287.
112 Koenig H, Goldstone A, Blume G, Lu CY. Testosterone-mediated sexual dimorphism of mitochondria and lysosomes in mouse kidney proximal tubules. Science. 1980; 209(4460):1023. 10.1126/science.7403864 7403864
113 Barthold SW. Chronic progressive nephropathy in aging rats. Toxicol Pathol. 1979; 7(1):1–6. 10.1177/019262337900700101
114 Baylis C. Age-dependent glomerular damage in the rat. Dissociation between glomerular injury and both glomerular hypertension and hypertrophy. Male gender as a primary risk factor. J Clin Invest. 1994; 94(5):1823–1829. 10.1172/JCI117531 7962527
115 Linkswiler H, Reynolds MS, Baumann CA. Factors affecting proteinuria in the rat. Am J Physiol. 1952; 168(2):504–508. 10.1152/ajplegacy.1952.168.2.504 14903168
116 Keegan CE, Hammer GD. Recent insights into organogenesis of the adrenal cortex. Trends Endocrinol Metab. 2002; 13(5):200–208. 10.1016/S1043-2760(02)00602-1 12185666
117 van Weerden WM, Bierings HG, Van Steenbrugge GJ, De Jong FH, Schröder FH. Adrenal glands of mouse and rat do not synthesize androgens. Life Sci. 1992; 50(12):857–861. 10.1016/0024-3205(92)90204-3 1312193
118 Huang C-C, Kang Y. The transient cortical zone in the adrenal gland: The mystery of the adrenal X-zone. J Endocrinol. 2019; 241(1):R51–R63. 10.1530/JOE-18-0632 30817316
119 Greaves P. Endocrine glands. Histopathology of Preclinical Toxicity Studies. 4th ed. Boston: Academic Press; 2012. Chapter 13; p. 725–797. 10.1016/B978-0-444-53856-7.00013-0
120 Hirokawa N, Ishikawa H. Electron microscopic observations on postnatal development of the X zone in mouse adrenal cortex. Z Anat Entwickl Gesch. 1974; 144(1):85–100. 10.1007/BF00518635 4368660
121 Blystone CR, Elmore SA, Witt KL, Malarkey DE, Foster PMD. Toxicity and carcinogenicity of androstenedione in F344/N rats and B6C3F1 mice. Food Chem Toxicol. 2011; 49(9):2116–2124. 10.1016/j.fct.2011.05.026 21651954
122 Gannon AL, O’Hara L, Mason IJ, Jørgensen A, Frederiksen H, Curley M, Milne L, Smith S, Mitchell RT, Smith LB. Androgen receptor is dispensable for x-zone regression in the female adrenal but regulates post-partum corticosterone levels and protects cortex integrity. Front Endocrinol (Lausanne). 2021; 11:599869. 10.3389/fendo.2020.599869 33584538
123 Matsuura S, Suzuki K. Morphological changes in the submandibular glands and in the X zone of the adrenal gland following ovariectomy in mice. Cell Tissue Res. 1986; 246(3):549–556. 10.1007/BF00215195 3791382
124 Howard E, Gengradom S. The effects of ovariectomy and administration of progesterone on the adrenal x-zone and the uterus. Endocrinology. 1940; 26(6):1048–1052. 10.1210/endo-26-6-1048
125 Zhao D, Liao Y, Zhang Z. Toxicity of ionic liquids. Clean (Weinh). 2007; 35(1):42–48. 10.1002/clen.200600015
126 Bernot RJ, Kennedy EE, Lamberti GA. Effects of ionic liquids on the survival, movement, and feeding behavior of the freshwater snail, Physa acuta. Environ Toxicol Chem. 2005; 24(7):1759–1765. 10.1897/04-614R.1 16050594
127 Couling DJ, Bernot RJ, Docherty KM, Dixon JK, Maginn EJ. Assessing the factors responsible for ionic liquid toxicity to aquatic organisms via quantitative structure–property relationship modeling. Green Chem. 2006; 8(1):82–90. 10.1039/B511333D
128 Kumari P, Pillai VVS, Benedetto A. Mechanisms of action of ionic liquids on living cells: The state of the art. Biophys Rev. 2020; 12(5):1187–1215. 10.1007/s12551-020-00754-w 32936423
129 Wang X, Ohlin CA, Lu Q, Fei Z, Hu J, Dyson PJ. Cytotoxicity of ionic liquids and precursor compounds towards human cell line HeLa. Green Chem. 2007; 9(11):1191–1197. 10.1039/b704503d
130 National Toxicology Program (NTP). Tox21 assays. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2021. https://sandbox.ntp.niehs.nih.gov/tox21-activity-browser/ [accessed May 4, 2021]
131 Hsieh JH, Sedykh A, Huang R, Xia M, Tice RR. A data analysis pipeline accounting for artifacts in Tox21 quantitative high-throughput screening assays. J Biomol Screen. 2015; 20(7):887–897. 10.1177/1087057115581317 25904095
132 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 2734160, 1-Ethyl-3-methylimidazolium chloride. Bethesda, MD: National Library of Medicine. https://pubchem.ncbi.nlm.nih.gov/compound/2734160
133 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 2734161, 1-Butyl-3-methylimidazolium chloride. Bethesda, MD: National Library of Medicine. https://pubchem.ncbi.nlm.nih.gov/compound/2734161
134 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 19876500, 1-Butyl-3-methylpyridinium Chloride. Bethesda, MD: National Library of Medicine. https://pubchem.ncbi.nlm.nih.gov/compound/19876500
135 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 2734171, n-Butylpyridinium chloride. Bethesda, MD: National Library of Medicine. https://pubchem.ncbi.nlm.nih.gov/compound/2734171
136 Arning J, Stolte S, Böschen A, Stock F, Pitner W-R, Welz-Biermann U, Jastorff B, Ranke J. Qualitative and quantitative structure activity relationships for the inhibitory effects of cationic head groups, functionalised side chains and anions of ionic liquids on acetylcholinesterase. Green Chem. 2008; 10(1):47–58. 10.1039/B712109A
137 Stolte S, Arning J, Bottin-Weber U, Müller A, Pitner W-R, Welz-Biermann U, Jastorff B, Ranke J. Effects of different head groups and functionalised side chains on the cytotoxicity of ionic liquids. Green Chem. 2007; 9(7):760–767. 10.1039/B615326G
138 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
139 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
140 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
141 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117