# Discussion

Since their nomination to the National Toxicology Program (NTP), the use of ionic liquids (ILs) in commercial processes and consumer products has expanded. ILs are finding their way into many households through electronics, batteries, perfumes, haircare products, pharmaceuticals, and antimicrobial cleaning agents as the movement for more “green” and “natural” consumer products gains momentum.^3,39,40,107,108^ Occupational exposure is also increasing as ILs are used to replace volatile organic compounds in many new and existing industrial applications.^2,5^ Despite the potential for increased human exposure, limited mammalian toxicity data are available for this class of chemicals. To address this data gap, NTP evaluated the in vivo toxicity of four ILs—1-ethyl-3-methylimidazolium chloride (Emim-Cl), 1-butyl-3-methylimidazolium chloride (Bmim-Cl), 1-butyl-1-methylpyrrolidinium chloride (Bmpy-Cl), and n-butylpyridinium chloride (NBuPy-Cl) —in 2-week and 3-month drinking water studies in rats and mice. These studies facilitate comparison of toxicity among the three most common cations used in ILs (imidazolium, pyrrolidinium, and pyridinium) and among differing alkyl side chain lengths.

In the 2-week studies, rats and mice were exposed to various concentrations of Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl in drinking water. This oral exposure route was used to simulate exposure to ILs through contamination of public water supplies.^109,110^ All animals survived until the end of the 2-week exposure period. Notably, for each of the four ILs, lower mean body weights of exposed animals were directly related to lower water consumption, which in turn was related to the concentration of the IL tested. Furthermore, clinical findings, including thinness and ruffled fur, were considered related to lower body weight rather than direct toxicity. At an equivalent exposure concentration (3 mg/mL), Bmim-Cl-exposed male and female rats exhibited the lowest water consumption and terminal mean body weights compared to the control groups, followed by rats exposed to NBuPy-Cl, Bmpy-Cl, and then Emim-Cl. Water consumption by, and terminal mean body weights of, male and female mice at 3 mg/mL followed a similar pattern. Thus, lower terminal mean body weights of IL-exposed rats and mice were possibly related to poor palatability of the ILs, resulting in lower water consumption.

While estimated chemical intake increased as IL concentrations in drinking water increased, chemical intake did not increase in direct proportion to exposure concentration because of the lower water consumption at higher IL concentrations. Although feed consumption was not measured, previous research suggests that poor palatability of a compound in drinking water can negatively affect both water and feed consumption, thereby reducing body weight gain.^111^ Under these circumstances, it is difficult to determine whether lower terminal mean body weights resulted primarily from IL-induced toxicity or were secondary to dehydration or poor appetite. Other endpoints observed across all ILs at the highest exposure concentrations, such as organ weight changes, similarly appear to reflect lower mean body weights and potentially decreased nutritional and caloric intake. Body weight and water consumption results from the 2-week range-finding study enabled selection of exposure concentrations for the 3-month drinking water studies in rats and mice.

As a guideline toxicity study, the 3-month exposure studies assessed specific endpoints of toxicity, namely: mortality, body weights, water consumption, organ weights, clinical chemistry, hematology, vaginal cytology, histopathology, and genotoxicity. There were no significant toxicological effects of IL exposure on mortality, clinical chemistry, hematology, vaginal cytology, or genotoxicity; details on these data are presented in the results, Appendix D, and Appendix E. Endpoints significantly affected by IL exposure (body weights, water consumption, organ weights, and histopathology) are further discussed below.

Exposure of rats and mice to Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl for 3 months resulted in an overarching pattern of lower mean body weights and water consumption similar to the 2-week studies. In general, water consumption by both rats and mice exposed to ILs for 3 months was lower than water consumption by control animals. Often, this observation was exposure concentration-dependent, with rats consuming on average 54%–80% of the control groups’ water consumption at the highest IL exposure concentrations (10 mg/mL Emim-Cl, 1 mg/mL Bmim-Cl, 3 mg/mL Bmpy-Cl in males, 6 mg/mL Bmpy-Cl in females, 3 mg/mL NBuPy-Cl) and mice consuming 56%–87% of the control groups’ water consumption at the highest IL exposure concentrations (30 mg/mL Emim-Cl, 3 mg/mL Bmim-Cl, 10 mg/mL Bmpy-Cl in males, 6 mg/mL Bmpy-Cl in females, 6 mg/mL NBuPy-Cl). Despite both species consuming less water with increased IL exposure concentrations, body weight changes were more variable and did not always decrease as IL exposure concentration increased. These body weight changes were potentially related to the ingested dose. Estimated compound consumption was increased at higher exposure concentrations but not always in direct proportion to the exposure concentration because of decreased water consumption. Estimated compound consumption values show that mice received a higher dose of ILs than rats; for example, rats exposed to 3 mg/mL Emim-Cl, Bmpy-Cl, or NBuPy-Cl consumed an estimated average of 171–258 mg/kg/day, whereas mice exposed to 3 mg/mL of these ILs consumed an estimated average of 310–403 mg/kg/day. For each of these exposed groups, males consumed an estimated 6%–11% less compound than females.

Changes in organ weights were observed at the highest exposure concentration of most ILs for rats and mice. These changes followed the pattern of lower body weights with higher IL exposure, which coincided with lower water consumption. In a few instances, in which absolute organ weight decreases were observed, these findings were not accompanied by histological changes in rats or mice; thus, their toxicological significance is not clear.

Histopathological results showed species- and sex-specific responses to the highest exposure concentrations of ILs. Neither male nor female rats exposed to Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl displayed any significant histopathological findings. Mice, however, had lesions in the kidney and adrenal gland (discussed in detail below). It is unclear whether this species-specific difference resulted from higher internal doses in mice compared to rats at the same exposure concentration, or higher sensitivity of mice tissues to ILs. Interestingly, the lesions all suggest steroid, potentially androgen, perturbation following IL exposure.

Exposure to high concentrations of ILs resulted in kidney lesions in both male and female mice. At the highest tested exposure concentrations of Emim-Cl (30 mg/mL), Bmpy-Cl (10 mg/mL), and NBuPy-Cl (6 mg/mL), male mice displayed cytoplasmic alteration in the kidney. This diagnosis is defined by a reduction in the renal tubular cytoplasmic vacuoles that are normally present in certain strains of young male mice but are uncommon in female mice or in male or female rats. The vacuoles are thought to be autophagic and involved in the sequestration and degradation of organelles associated with the normal degeneration of renal tubular epithelial cells.^105,112^ In male mice, these vacuoles decrease and eventually disappear as the animal ages. The accumulation of lysosomes in the outer renal tubules of male mice, seen microscopically as vacuolation, has been shown to depend on endogenous testosterone; female mice administered testosterone accumulated lysosomes, resulting in kidneys phenotypically similar to male mice.^112^ In the present study, there were markedly fewer vacuoles (cytoplasmic alteration) in male mice in the highest exposure concentration groups for 3 of the 4 ILs (Emim-Cl, Bmpy-Cl, and NBuPy-Cl), such that the kidneys of the male mice were phenotypically similar to the kidneys of female mice. This phenotypic observation was also true for one male mouse at the highest exposure of Bmim-Cl. This lack of testosterone-responsive vacuolation in the renal cortical tubules in male mice after exposure to all four ILs suggests a potential perturbation of androgens.

Another kidney lesion observed in IL-exposed mice was chronic progressive nephropathy (CPN). The incidences of CPN were significantly increased at the highest exposure concentration in Emim-Cl- and NBupy-Cl-exposed male mice; a positive trend was also observed in Bmim-Cl-exposed male mice as well as Bmim-Cl- and NBuPy-Cl-exposed female mice. CPN is primarily tubulointerstitial nephritis, common as a background lesion in rats, but also occurring in mice.^104^ The incidence and severity of CPN are generally greater in rats than in mice, and greater in males than in females.^113^ No evidence of exposure-related increases in the incidence or severity of CPN in rats was noted in this study; however, a higher incidence was found in male mice than in female mice. The etiology of CPN is unknown, but factors such as xenobiotic administration, genetic background, increased age, protein content of diet, and hormones can modulate its occurrence and severity.^113^ The presence of androgens has also been associated with the risk of developing CPN.^114^ In male rats, CPN severity is enhanced by the administration of testosterone and abrogated by castration.^114,115^ As with the cytoplasmic alteration in the kidney, the lack of sexually dimorphic enhancement of CPN severity in male rats compared to female rats in this study also suggests a perturbation of androgens.

Numerous female mice exposed to each of the four ILs displayed a persistent X-zone in their adrenal gland, whereas no adrenal gland lesions were observed in male mice. Mammalian adrenal glands have three morphologically distinct zones with separate functions: the outer zona glomerulosa that secretes mineralocorticoids, such as aldosterone; an intermediate zone fasciculata that secretes glucocorticoids, such as cortisol; and an inner zona reticularis that secretes adrenal androgens, mainly dehydroepiandrosterone (DHEA).^116^ Mice lack a functional, distinct zona reticularis and lack 17α-hydroxylase (CYP17), the key enzyme in the production of androgenic steroids, and therefore mice do not synthesize adrenal androgens.^117^ Instead, mice have a unique transient region, called the “X-zone,” at the junction of the cortex and medulla. The analogous structure in humans is the “fetal zone.”^116,118^ In mice, the X-zone appears a few days after birth and is fully developed by weaning. The cells in this region are denser and more basophilic than the cells in the adjacent zona fasciculata.^119^ In male mice, the X-zone disappears at approximately 5 weeks of age with the onset of puberty and does not undergo vacuolization. In female mice, the X-zone reaches its maximum size at about 9 weeks of age and then gradually regresses in virgins or rapidly at first pregnancy. During the process of regression in female mice, these cells develop lipid droplets with peculiar mitochondrial complexes and a smooth endoplasmic reticulum characteristic of steroid-secreting cells.^120^ There is a delay in the involution of the X-zone in prepubertal male and female mice following gonadectomy and, in female mice, hypophysectomy will result in X-zone involution.^119^ Androgen administration, such as androstenedione, will result in the rapid disappearance of the X-zone in female mice, and removing androgens with ovariectomy will prolong the persistence of the X-zone in female mice.^121-124^ While the function of the X-zone is unknown, its normal development and regression are mediated by a variety of factors, including sex steroid hormones, luteinizing hormones, and thyroid hormones.^118^ This is the first known study in which exposure to ILs has been linked to this type of lesion in the adrenal gland.

The toxicity of ILs is dependent on the anion, cation, concentration, substituents, and the investigated biosystem.^108^ Most studies examining the toxicity of ILs use in silico or in vitro approaches, and early in vivo toxicity studies more commonly used nonmammalian animal models.^108^ Although somewhat limited by the number of chemicals evaluated here, this study can be used to make general comparisons to better understand in vivo mammalian toxicity associated with different cations or alkyl side chain length. Specifically, body weight and histological changes in response to IL exposure can be compared among the four ILs included in this study. Rats only had significant changes in terminal mean body weights after exposure to two of the four ILs. These changes were within 12% of the control groups and occurred at the higher exposure concentrations (1–6 mg/mL), for which average daily water consumption was 48%–84% of the control groups. Furthermore, no evidence of histopathological changes was found in rats following the 3-month exposure period. The rat studies, therefore, did not allow comparisons that might support conclusions relating cation type or alkyl chain length to toxicity. In contrast, mice exposed to all four ILs did exhibit body weight and histopathological changes, providing an opportunity to compare the toxicity of each IL (by cation type or alkyl chain length).

Zhao et al. first proposed that imidazolium-based ILs with longer alkyl chain substituents are more toxic because longer alkyl side chains increase chemical hydrophobicity.^125^ This hypothesis was investigated by Bailey and colleagues, who evaluated the potential for Emim-Cl, Bmim-Cl, and the longer chain 1-decyl-3-methylimidazolium chloride (Dmim-Cl) to induce developmental toxicity in pregnant CD-1 mice.^68^ Bailey et al.^68^ reported that Emim-Cl was not toxic, but ILs with longer alkyl chain lengths had increased toxicity. Using short-term in vitro inhibition respiration assays, Gomez-Herrero et al.^57^ further showed the toxicity of imidazolium-based ILs increased as alkyl chain length increased. The imidazolium-based IL with the shortest alkyl chain was 24-fold less toxic than the IL with the longest alkyl chain; Emim-Cl (2 carbons), Bmim-Cl (4 carbons), 1-hexyl-3-methylimidazolium chloride (Hmim-Cl; 6 carbons), and 1-octyl-3-methylimidazolium chloride (Omim-Cl; 8 carbons) had median effective concentration (EC_50_) values of 4.19, 1.79, 0.91, and 0.17 mM, respectively. This pattern of toxicity is corroborated by several other in vitro assays and a myriad of other biological systems, such as microorganisms, plants, and human cell lines.^4,57,58,126-129^ In the present studies, mice exposed to Bmim-Cl experienced significantly decreased terminal mean body weights and/or histopathological changes at exposure concentrations 10 times lower than mice exposed to Emim-Cl, supporting the hypothesis that ILs with longer alkyl chains are more toxic. Specifically, male mice exposed to Emim-Cl had a lowest-observed-effect level (LOEL) of 10 mg/mL when focusing on significant terminal mean body weight changes and 30 mg/mL when focusing on histopathological changes (Figure 12). Male mice exposed to Bmim-Cl had a LOEL of 3 mg/mL for significant terminal mean body weight changes; male mice exposed to Bmim-Cl had no significant histopathological changes and therefore no corresponding LOEL could be determined (Figure 12). Female mice exposed to Emim-Cl had a LOEL of 30 mg/mL when focusing on significant terminal mean body weight changes and histopathological changes, whereas female mice exposed to Bmim-Cl had a LOEL of 3 mg/mL for the same endpoints. Although no deaths were reported in Bmim-Cl-exposed rats or mice in this study, Landry et al.^46^ estimated an oral median lethal dose (LD_50_) for Bmim-Cl of 550 mg/kg in female Fischer 344 (F344) rats. Rats and mice in the present study were exposed to Emim-Cl at higher concentrations and much higher estimated average internal doses (up to 691 mg/kg/day in rats and 2,457 mg/kg/day in mice) than the reported Bmim-Cl LD_50_, but no deaths were reported for this chemical, suggesting Emim-Cl, with a 2-carbon alkyl side chain, may be better tolerated and less toxic than Bmim-Cl, with a 4-carbon alkyl side chain.

Figure 12

Lowest-observed-effect Levels Related to Significant Decreases in Terminal Mean Body Weight and/or Histopathological Changes in Male and Female Mice

Emim-Cl = 1-ethyl-3-methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

Additional research by NTP investigating this question in a dermal sensitization study demonstrated similar results; in vivo and in vitro assays for skin sensitization determined that Emim-Cl was not toxic, whereas Bmim-Cl was classified as a weak sensitizer.^69^ The relationship between alkyl chain length and toxicity is further supported by high-throughput in vitro screening assays conducted by NTP on 197 ILs. In general, as IL alkyl chain length increases (up to 18 carbons), toxicity and activity in Tox21 assays increase.^130,131^ It should be noted that the four ILs tested in this report had very weak activities in these in vitro assays,^132-135^ potentially supporting the conclusion of their relatively low toxicity in vivo. One caveat to the present studies is that while differing alkyl chain lengths were tested for methylimidazoliums, ILs with <5 carbons (e.g., both Emim-Cl [2 carbons] and Bmim-Cl [4 carbons]) are typically thought to have limited toxicity, whereas ILs with >6 carbons are thought to have linearly increased toxicity up to 10 carbons, wherein toxicity plateaus.^62,63^ It may be worthwhile, therefore, to assess in vivo mammalian toxicity in ILs with longer alkyl chain lengths in future studies. Gomez-Herrero et al.^57^ suggested longer alkyl chains may interact with membrane proteins as well as with the lipid bilayer, altering integrity and native state of proteins in the membrane. Interestingly, this ability of some long-chain ILs to perturb cell membranes can be mitigated by rational design, and this quality is being utilized in the pharmaceutical industry to enhance transcellular and paracellular drug transport.^108^

Another goal of the present studies was to compare the toxicity of different cations (i.e., imidazolium, pyrrolidinium, and pyridinium). To ensure the cation could be properly evaluated, Bmim-Cl, Bmpy-Cl, and NBuPy-Cl all contained a 4-carbon alkyl side chain and the same anion. Various studies have suggested that aromatic-based ILs, such as imidazolium and pyridinium, are more toxic in vitro than nonaromatic ILs, such as pyrrolidinium, due to increased hydrophobicity of head groups.^4,57,58^ Quantitative structure-property relationship (QSPR) modeling predicts that imidazolium cations are more toxic than pyridinium cations due to the difference in the number of nitrogen atoms.^4,127^ In NTP studies investigating these ILs for dermal sensitization, both Bmim-Cl and Bmpy-Cl were classified as weak sensitizers, whereas NBuPy-Cl was classified as an irritant,^69^ but results from the Frawley et al. study did not distinguish toxicity by cation type.

In the 3-month drinking water study presented here, toxicological findings varied across male and female mice for all three cation types. When comparing body weight changes, male mice exposed to Bmim-Cl (imidazolium) displayed significant changes at lower exposure concentrations than NBuPy-Cl (pyridinium) or Bmpy-Cl (pyrrolidinium) (Figure 12); significantly decreased terminal mean body weights were observed at 3, 6, and 10 mg/mL in Bmim-Cl-, NBuPy-Cl-, and Bmpy-Cl-exposed male mice, respectively. In contrast, while no significant histopathological changes were observed in Bmim-Cl-exposed male mice, NBuPy-Cl- and Bmpy-Cl-exposed male mice had significant increases in the incidence of kidney lesions at 6 mg/mL and 10 mg/mL, respectively (note these are the same LOELs as for terminal mean body weight changes). In female mice, a significant decrease in terminal mean body weight was observed in the groups exposed to 3 mg/mL Bmim-Cl or NBuPy-Cl, but not Bmpy-Cl. Significant increases in adrenal lesions were also observed in all three cation groups at 3 mg/mL in Bmim-Cl- and Bmpy-Cl-exposed female mice and at 6 mg/mL in NBuPy-Cl-exposed female mice (the same as in NBuPy-Cl-exposed males). On the basis of these endpoints and on the exposure concentrations tested, it is unclear whether imidazolium-, pyrrolidinium- or pyridinium-based IL exposure is most toxic.

In the aforementioned Tox21 high-throughput in vitro assays conducted by NTP, cation type was not a good predictor of cytotoxicity or activity. Other researchers have speculated that the toxicity of ILs with a bioactive cation may depend more on the cationic head group than on the alkyl side chain, whereas toxicity in less bioactive cations (e.g., imidazolium, pyridinium) may be modulated more strongly by the side chain.^108,136^ For example, in the promyelocytic leukemia rat cell line IPC-81, toxicity of imidazolium, pyridinium, piperidinium, pyrrolidinium, and morpholinium are similar.^108,137^ Therefore, it is reasonable that the cations tested in the current study exhibit minimal differences in toxicity.

Overall, the results from this comparative study suggest that Emim-Cl, Bmim-Cl, Bmpy-Cl, and NBuPy-Cl in drinking water have minimal effects on rats and mice at low exposure concentrations (<3 mg/mL). Exposure to higher IL concentrations (≥3 mg/mL) results in lower body weights and nonneoplastic lesions in the kidneys of male and female mice and in the adrenal glands of female mice. The lowest-observed-effect levels (LOELs) were determined using these data. The LOELs were assigned as 10 mg/mL for Emim-Cl-exposed male mice, 3 mg/mL for Bmim-Cl-exposed male mice, 10 mg/mL for Bmpy-Cl-exposed male mice, and 6 mg/mL for NBuPy-Cl-exposed male mice. The LOELs for female mice differed slightly. The LOELs were 30 mg/mL for Emim-Cl-exposed female mice, 3 mg/mL for Bmim-Cl-exposed female mice (the same as for Bmim-Cl-exposed male mice), 3 mg/mL for Bmpy-Cl-exposed female mice, and 3 mg/mL for NBuPy-Cl-exposed female mice. These studies indicate that IL-induced toxicity may be attributable to alkyl chain length and cation type. ILs with longer alkyl chains typically exhibit increased toxicity compared to ILs with shorter alkyl chains. In this report, mice exposed to Bmim-Cl (an IL with a 4-carbon alkyl chain) had a lower LOEL than did mice exposed to Emim-Cl (an IL with a 2-carbon alkyl chain). The difference in toxicity among cations (imidiazolium vs. pyrrolidinium vs. pyridinium), however, is less clear and is both sex- and endpoint-dependent.