# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-103.^102^

## Two-week Studies

### Rats and Mice

In the 2-week studies, survival of rats and mice was not affected by exposure to 1-ethyl-3-methylimidazolium chloride (Emim-Cl), 1-butyl-3-methylimidazolium chloride (Bmim-Cl), 1-butyl-1-methylpyrrolidinium chloride (Bmpy-Cl), or n-butylpyridinium chloride (NBuPy-Cl). Clinical observations, including thinness and ruffled fur, were common in rats and mice exposed to higher concentrations of each ionic liquid (IL), except for Bmim-Cl- and Bmpy-Cl-exposed rats, which did not have any exposure-related clinical findings (Appendix E).

The clinical findings may have been related to lower body weights. An exposure concentration-dependent decrease in body weight was observed in most groups of male and female rats and mice exposed to ILs; terminal mean body weights of the highest exposed groups of rats and mice were often lower than those of the control groups (Table 5). Terminal mean body weights following Emim-Cl exposure were 32%–38% of the control groups in male and female rats and approximately 54% of the control groups in male and female mice at the highest concentration (100 mg/mL). In Bmim-Cl-exposed male and female animals, terminal mean body weights were 85%–86% and 81%–87% of the control groups in rats and mice, respectively, at the highest concentrations (3 mg/mL rats, 6 mg/mL mice). Terminal mean body weights of Bmpy-Cl-exposed male and female rats were approximately 83%–91% of the control groups and 86% of the control group in female mice at the highest concentrations (6 mg/mL rats, 10 mg/mL mice). Terminal mean body weights of male mice were unaffected by Bmpy-Cl administration. In NBuPy-Cl-exposed male and female rats, terminal mean body weights were approximately 67%–68% of the control groups at the highest concentration (6 mg/mL). Terminal mean body weights of male and female mice were approximately 89% of the control groups at the highest concentration (6 mg/mL).

Table 5 Summary of Terminal Mean Body Weights of Male and Female Rats and Mice in the Two-week Drinking Water Study of Ionic Liquids

| 0 mg/mL | 0.3 mg/mL | | 1 mg/mL | | 3 mg/mL | | 6 mg/mL | | 10 mg/mL | | 30 mg/mL | | 100 mg/mL
| Av. Wt. (g) | Av. Wt. (g) | Wt. (% of Controls) | Av. Wt. (g) | Wt. (% of Controls) | Av. Wt. (g) | Wt. (% of Controls) | Av. Wt. (g) | Wt. (% of Controls) | Av. Wt. (g) | Wt. (% of Controls) | Av. Wt. (g) | Wt. (% of Controls) | Av. Wt. (g) | Wt. (% of Controls)
Rats ^a^
Male
Emim-Cl | 278.3 | –^b^ | – | – | – | 276.9 | 99.5 | – | – | 260.7 | 93.7 | 170.3 | 61.2 | 90.3 | 32.4
Bmim-Cl | 278.3 | 280.5 | 100.8 | 272.0 | 97.7 | 235.9 | 84.7 | – | – | – | – | – | – | – | –
Bmpy-Cl | 278.3 | – | – | 281.0 | 101.0 | 268.8 | 96.6 | 229.8 | 82.6 | – | – | – | – | – | –
NBuPy-Cl | 278.3 | – | – | 282.6 | 101.5 | 257.8 | 92.6 | 189.9 | 68.2 | – | – | – | – | – | –
Female
Emim-Cl | 183.1 | – | – | – | – | 189.7 | 103.6 | – | – | 175.8 | 96.0 | 128.0 | 69.9 | 69.6 | 38.0
Bmim-Cl | 183.1 | 181.2 | 98.9 | 179.5 | 98.0 | 157.2 | 85.9 | – | – | – | – | – | – | – | –
Bmpy-Cl | 183.1 | – | – | 184.5 | 100.7 | 179.2 | 97.9 | 166.8 | 91.1 | – | – | – | – | – | –
NBuPy-Cl | 183.1 | – | – | 176.5 | 96.4 | 173.7 | 94.9 | 122.8 | 67.0 | – | – | – | – | – | –
Mice
Male
Emim-Cl | 26.3 | – | – | – | – | 26.5 | 100.8 | – | – | 25.6 | 97.6 | 24.5 | 93.3 | 14.3 | 54.3
Bmim-Cl | 26.3 | – | – | 26.8 | 102.1 | 25.4 | 96.7 | 21.4 | 81.3 | – | – | – | – | – | –
Bmpy-Cl | 26.3 | – | – | – | – | 26.1 | 99.5 | 26.6 | 101.3 | 25.2 | 96.0 | – | – | – | –
NBuPy-Cl | 26.3 | – | – | 26.0 | 98.9 | 25.5 | 97.1 | 23.4 | 89.3 | – | – | – | – | – | –
Female
Emim-Cl | 20.5 | – | – | – | – | 20.0 | 97.8 | – | – | 20.5 | 100.4 | 18.5 | 90.2 | 11.0 | 53.9
Bmim-Cl | 20.5 | – | – | 19.5 | 95.1 | 19.1 | 93.4 | 17.9 | 87.3 | – | – | – | – | – | –
Bmpy-Cl | 20.5 | – | – | – | – | 19.9 | 97.5 | 18.5 | 90.3 | 17.6 | 86.1 | – | – | – | –
NBuPy-Cl | 20.5 | – | – | 18.1 | 88.7 | 19.6 | 95.8 | 18.3 | 89.2 | – | – | – | – | – | –

Emim-Cl = 1-ethyl-3-methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

^a^ N = 10 animals/vehicle control group; n = 5 animals/exposed group.

^b^ Exposures at this concentration were not conducted for this group.

Lower mean body weights were associated with lower water consumption. Test article palatability likely directly affected mean water consumption and indirectly affected mean body weights. In general, mean water consumption by exposed rats was lower compared to control animals than consumption by exposed mice; this difference between rats and mice was most evident at the highest exposure concentrations for each IL (Table 6). Compared to the respective control groups, mean water consumption at the highest exposure concentration was 45%–46% by Bmim-Cl-exposed rats (3 mg/mL), 46%–57% by Bmim-Cl-exposed mice (6 mg/mL), 50%–55% by Bmpy-Cl-exposed rats (6 mg/mL), 25%–73% by Bmpy-Cl-exposed mice (10 mg/mL), 36%–38% by NBuPy-Cl-exposed rats (6 mg/mL), and 49%–71% by NBuPy-Cl-exposed mice (6 mg/mL). Water consumption values were much lower for Emim-Cl-exposed rats and mice, which were exposed to higher concentrations of the test article in drinking water. In male and female rats exposed to 30 or 100 mg/mL Emim-Cl, mean water consumption values were approximately 40% or 5%, respectively, of those of the control groups. In mice exposed to the same concentrations of Emim-Cl, mean water consumption values were 45%–69% (males) and 21%–57% (females) of the control groups. Due to lower water consumption by the higher exposed groups, compound consumption did not increase proportionally with higher exposure concentrations of each IL in water. Compound consumption values for each IL are presented as supplemental data in Appendix E.

Table 6 Summary of Water Consumption of Male and Female Rats and Mice in the Two-week Drinking Water Study of Ionic Liquids

| 0 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL | 10 mg/mL | 30 mg/mL | 100 mg/mL
Rats (g/animal/day)^a^
Male
Emim-Cl | 36.0 | –^b^ | – | 29.1 | – | 21.8 | 14.5 | 1.1
Bmim-Cl | 36.0 | 27.7 | 27.0 | 16.3 | – | – | – | –
Bmpy-Cl | 36.0 | – | 29.3 | 25.8 | 18.1 | – | – | –
NBuPy-Cl | 36.0 | – | 25.5 | 19.4 | 12.9 | – | – | –
Female
Emim-Cl | 22.6 | – | – | 21.5 | – | 13.4 | 9.7 | 1.8
Bmim-Cl | 22.6 | 23.5 | 17.5 | 10.4 | – | – | – | –
Bmpy-Cl | 22.6 | – | 20.0 | 16.6 | 12.4 | – | – | –
NBuPy-Cl | 22.6 | – | 16.8 | 12.5 | 8.5 | – | – | –
Mice (g/animal/day)
Male
Emim-Cl | 4.9 | – | – | 4.8 | – | 4.4 | 3.4 | 2.2
Bmim-Cl | 4.9 | – | 4.6 | 3.8 | 2.8 | – | – | –
Bmpy-Cl | 4.9 | – | – | 4.5 | 4.5 | 3.6 | – | –
NBuPy-Cl | 4.9 | – | 4.3 | 4.5 | 2.4 | – | – | –
Female
Emim-Cl | 2.8 | – | – | 2.6 | – | 2.7 | 1.6 | 0.6
Bmim-Cl | 2.8 | – | 2.0 | 1.5 | 1.3 | – | – | –
Bmpy-Cl | 2.8 | – | – | 2.1 | 1.7 | 0.7 | – | –
NBuPy-Cl | 2.8 | – | 0.9 | 2.2^c^ | 2.0^c^ | – | – | –

Emim-Cl = 1-ethyl-3-methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

^a^ Mean water consumption data from the last day of the study; n = 5 animals/group.

^b^ Exposures at this concentration were not conducted for this group.

^c^ Data missing for last day of study; mean for week 2 was used.

Several organ weight fluctuations were observed in rats and mice exposed to ILs, most of which occurred in animals exposed at the highest IL exposure concentrations. Compared to control animals, changes in mean organ weights were often characterized by lower absolute weight and higher relative weight, which corresponded to lower mean body weights. The largest organ weight differences from the control group were recorded in the Emim-Cl and NBuPy-Cl studies, which also had the greatest reduction in mean water consumption and terminal mean body weights compared to control animals. Animals exposed to Bmim-Cl or Bmpy-Cl exhibited limited organ weight differences from the control group, which were chemical- and sex-specific. Organ weight data for each IL can be found in Appendix E.

Although a formal NTP review of histopathological findings was not conducted for the 2-week studies, several lesions were found to be common in animals exposed to higher IL concentrations in both sexes and species. Lesions such as glycogen depletion of the liver, thymic atrophy, cellular depletion of the spleen, and degeneration of the testes were most common across the ILs. It is difficult to determine whether these changes were related to chronic stress and/or lower water (or hypothesized feed) consumption and lower body weights rather than a direct toxic effect from IL exposure for 2 weeks.^103^ Histopathological findings for each IL can be found in Appendix E.

### Exposure Concentration Selection Rationale for the Three-month Studies

Lower mean body weights and water consumption compared to control animals were the two primary toxicity parameters that guided exposure concentration selection for the 3-month IL studies. Rats appeared to be more sensitive to IL exposure in drinking water (i.e., lower water consumption and mean body weights), which was also taken into consideration for exposure concentration selection. In general, the top exposure concentrations selected for the 3-month studies demonstrated mean body weights within 10% of control animals and mean water consumption rates within 25% of control animals following the 2-week exposure period. The exposure concentrations selected for the 3-month studies are shown in Table 4. Exposure concentrations selected for Emim-Cl were higher than those for other ILs due to its apparently lower toxicity. Due to sex differences observed in the 2-week studies, different exposure concentrations were selected for males and females in the Bmpy-Cl studies.

## Three-month Studies

### Rats

#### 1-Ethyl-3-Methylimidazolium Chloride (Emim-Cl)

Male and female rats were exposed to Emim-Cl at concentrations of 0, 1, 3, or 10 mg/mL in drinking water. All rats survived to the end of the 3-month exposure period (Table 7), and no clinical observations related to Emim-Cl exposure were noted (Appendix E). Male and female mean body weights of all exposed groups remained within 10% of the mean body weights of the control groups throughout the course of study and were not significantly different at the end of the 3-month exposure period (Table 7; Figure 1; Appendix E).

Table 7 Summary of Survival and Mean Body Weights of Male and Female Rats in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride

Study Day^a^ | 0 mg/mL | | 1 mg/mL | | | 3 mg/mL | | | 10 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 147.0 | 10 | 147.3 | 100.2 | 10 | 146.5 | 99.6 | 10 | 147.7 | 100.4 | 10
8 | 196.9 | 10 | 196.7 | 99.9 | 10 | 198.1 | 100.6 | 10 | 189.0 | 96.0 | 10
15 | 242.8 | 10 | 243.6 | 100.3 | 10 | 243.9 | 100.5 | 10 | 232.6 | 95.8 | 10
22 | 262.7 | 10 | 263.1 | 100.1 | 10 | 247.6 | 94.2 | 10 | 249.7 | 95.0 | 10
29 | 304.0 | 10 | 302.1 | 99.4 | 10 | 302.9 | 99.6 | 10 | 292.3 | 96.2 | 10
36 | 328.4 | 10 | 327.6 | 99.8 | 10 | 328.9 | 100.1 | 10 | 316.8 | 96.5 | 10
43 | 344.0 | 10 | 345.3 | 100.4 | 10 | 346.0 | 100.6 | 10 | 334.3 | 97.2 | 10
50 | 361.8 | 10 | 363.3 | 100.4 | 10 | 363.8 | 100.6 | 10 | 353.2 | 97.6 | 10
57 | 373.1 | 10 | 376.1 | 100.8 | 10 | 376.6 | 100.9 | 10 | 366.0 | 98.1 | 10
64 | 384.8 | 10 | 388.6 | 101.0 | 10 | 389.2 | 101.1 | 10 | 375.0 | 97.4 | 10
71 | 393.1 | 10 | 399.9 | 101.7 | 10 | 401.1 | 102.0 | 10 | 383.3 | 97.5 | 10
78 | 403.5 | 10 | 410.6 | 101.8 | 10 | 410.6 | 101.8 | 10 | 391.9 | 97.1 | 10
85 | 415.3 | 10 | 423.0 | 101.9 | 10 | 424.0 | 102.1 | 10 | 402.2 | 96.8 | 10
EOS | 424.6 | 10 | 434.5 | 102.3 | 10 | 436.1 | 102.7 | 10 | 411.9 | 97.0 | 10
Female
1 | 109.7 | 10 | 111.1 | 101.3 | 10 | 108.1 | 98.6 | 10 | 108.6 | 99.0 | 10
8 | 139.6 | 10 | 140.1 | 100.4 | 10 | 136.2 | 97.6 | 10 | 129.3 | 92.6 | 10
15 | 161.7 | 10 | 164.9 | 102.0 | 10 | 157.0 | 97.1 | 10 | 150.0 | 92.8 | 10
22 | 178.8 | 10 | 182.5 | 102.0 | 10 | 172.4 | 96.4 | 10 | 163.5 | 91.4 | 10
29 | 190.2 | 10 | 195.0 | 102.5 | 10 | 182.8 | 96.1 | 10 | 176.4 | 92.8 | 10
36 | 205.0 | 10 | 211.2 | 103.0 | 10 | 198.4 | 96.7 | 10 | 190.0 | 92.6 | 10
43 | 214.4 | 10 | 221.3 | 103.2 | 10 | 208.8 | 97.4 | 10 | 200.4 | 93.5 | 10
50 | 221.4 | 10 | 227.9 | 102.9 | 10 | 214.3 | 96.8 | 10 | 205.2 | 92.7 | 10
57 | 225.9 | 10 | 234.6 | 103.9 | 10 | 223.3 | 98.9 | 10 | 212.8 | 94.2 | 10
64 | 232.5 | 10 | 242.2 | 104.2 | 10 | 224.9 | 96.7 | 10 | 219.7 | 94.5 | 10
71 | 240.7 | 10 | 243.9 | 101.3 | 10 | 231.6 | 96.2 | 10 | 225.6 | 93.8 | 10
78 | 245.0 | 10 | 250.1 | 102.1 | 10 | 235.4 | 96.1 | 10 | 228.9 | 93.4 | 10
85 | 247.4 | 10 | 252.8 | 102.2 | 10 | 240.7 | 97.3 | 10 | 234.3 | 94.7 | 10
EOS | 254.5 | 10 | 256.3 | 100.7 | 10 | 246.9 | 97.0 | 10 | 241.1 | 94.7 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 1

Growth Curves for Male and Female Rats in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride

Growth curves are shown for (A) males and (B) females.

Water consumption by male and female rats exposed to 3 or 10 mg/mL Emim-Cl was lower than that of control animals (Table 8). At 1 mg/mL, the mean water consumption was within 10% of the control groups for both males and females. At 3 mg/mL, mean water consumption ranged from 85% to 94% of the control group in males and from 78% to 89% of the control group in females (Appendix E). At the highest exposure concentration of 10 mg/mL, mean water consumption ranged from 71% to 83% of the control group in males and from 59% to 69% of the control group in females. Drinking water concentrations of 1, 3, and 10 mg/mL resulted in estimated average doses of 88, 237, and 668 mg Emim-Cl/kg body weight/day (mg/kg/day) for males and 104, 258, and 691 mg/kg/day for females.

Table 8 Summary of Water and 1-Ethyl-3-Methylimidazolium Chloride Consumption of Male and Female Rats in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 1 mg/mL | 3 mg/mL | 10 mg/mL | 1 mg/mL | 3 mg/mL | 10 mg/mL
Male
1 | 25.5 | 25.8 | 24.0 | 18.7 | 175.1 | 491.6 | 1,266.5
3 | 27.7 | 27.8 | 25.8 | 21.2 | 114.1 | 317.3 | 911.6
6 | 26.1 | 26.4 | 23.1 | 19.4 | 80.6 | 210.7 | 612.3
9 | 23.9 | 25.2 | 21.7 | 18.1 | 67.0 | 172.9 | 494.5
13 | 22.4 | 24.2 | 20.8 | 18.5 | 57.2 | 147.2 | 460.0
Female
1 | 19.4 | 20.0 | 16.8 | 12.9 | 180.0 | 466.3 | 1,188.3
3 | 19.2 | 19.8 | 15.6 | 12.7 | 120.1 | 298.1 | 846.8
6 | 20.0 | 20.8 | 16.3 | 12.4 | 98.5 | 246.5 | 652.8
9 | 18.7 | 19.7 | 15.7 | 12.0 | 84.0 | 210.9 | 564.0
13 | 17.7 | 19.5 | 15.8 | 12.3 | 77.1 | 197.0 | 525.0

^a^ Mean g of water consumed/animal/day.

^b^ Mg of 1-ethyl-3-methylimidazolium chloride consumed/kg body weight/day.

While terminal mean body weights of Emim-Cl-exposed rats were similar to those of control animals, a few organ weight differences were observed in both males and females (Appendix E). The only significant change was in females, wherein the relative right kidney weights were slightly increased in the 3 and 10 mg/mL groups compared to those of control animals (Table 9; Appendix E).

Table 9 Summary of Kidney Weights and Kidney-Weight-to-Body-Weight Ratios for Female Rats in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride^a,b^

| 0 mg/mL | 1 mg/mL | 3 mg/mL | 10 mg/mL
n | 10 | 10 | 10 | 10
Female
Terminal Body Wt. (g) | 254.5 ± 7.3 | 256.3 ± 7.1 | 246.9 ± 7.0 | 241.1 ± 5.6
Right Kidney
Absolute (g) | 0.84 ± 0.03 | 0.86 ± 0.03 | 0.87 ± 0.02 | 0.88 ± 0.02
Relative (mg/g) | 3.29 ± 0.06** | 3.36 ± 0.07 | 3.52 ± 0.07* | 3.64 ± 0.06**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

No changes in rat clinical chemistry parameters were attributable to Emim-Cl exposure (Appendix E). For hematology parameters measured at the end of the 3-month exposure period, significant decreases in the female white blood cell count and differential (i.e., leukocyte counts) were observed relative to control rats (Appendix E). The female control group leukocyte counts for the Emim-Cl study were higher than the control group leukocyte counts for the other three ILs, however, this can be explained by the inherently and relatively high inter- and intra-animal variability of baseline leukocyte counts. In addition, the Emim-Cl leukocyte changes were not observed in mice or male rats, and no histopathological changes were observed in the bone marrow or spleen. Although the decreases in leukocyte counts compared to the control rats appear at first to be exposure-related, they are probably due to biological variability among observed animals. No exposure-related changes were observed in the hematological parameters of male rats.

Estrous cycle length, number of cycles, and percentage of time spent in each respective stage of estrous were not affected by Emim-Cl exposure. Assessment of the lengths of diestrus, proestrus, and estrus using the continuous-time Markov model did not reveal any Emim-Cl-related differences in modeled stage lengths (Appendix E).

No exposure-related gross or histopathological changes were observed in male or female rats exposed to Emim-Cl (Appendix E).

#### 1-Butyl-3-Methylimidazolium Chloride (Bmim-Cl)

Male and female rats were exposed to Bmim-Cl at concentrations of 0, 0.1, 0.3, or 1 mg/mL in drinking water. All rats survived to the end of the 3-month exposure period (Table 10), and no exposure-related clinical observations were noted (Appendix E). Mean body weights of male and female exposed groups remained within 10% of the mean body weights of the control groups throughout the study and were not significantly different at the end of the 3-month exposure period (Table 10; Figure 2; Appendix E).

Table 10 Summary of Survival and Mean Body Weights of Male and Female Rats in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride

Study Day^a^ | 0 mg/mL | | 0.1 mg/mL | | | 0.3 mg/mL | | | 1 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 141.4 | 10 | 140.5 | 99.3 | 10 | 140.1 | 99.1 | 10 | 141.2 | 99.9 | 10
8 | 192.5 | 10 | 188.8 | 98.1 | 10 | 186.8 | 97.1 | 10 | 184.4 | 95.8 | 10
15 | 238.8 | 10 | 232.7 | 97.4 | 10 | 231.3 | 96.8 | 10 | 228.1 | 95.5 | 10
22 | 275.4 | 10 | 267.2 | 97.0 | 10 | 269.2 | 97.7 | 10 | 265.7 | 96.4 | 10
29 | 306.8 | 10 | 295.7 | 96.4 | 10 | 296.4 | 96.6 | 10 | 291.0 | 94.8 | 10
36 | 327.8 | 10 | 314.5 | 95.9 | 10 | 314.4 | 95.9 | 10 | 311.4 | 95.0 | 10
43 | 347.4 | 10 | 332.3 | 95.6 | 10 | 333.4 | 96.0 | 10 | 329.1 | 94.7 | 10
50 | 361.1 | 10 | 344.9 | 95.5 | 10 | 348.1 | 96.4 | 10 | 343.4 | 95.1 | 10
57 | 369.3 | 10 | 354.1 | 95.9 | 10 | 359.7 | 97.4 | 10 | 353.2 | 95.6 | 10
64 | 380.0 | 10 | 365.2 | 96.1 | 10 | 368.3 | 96.9 | 10 | 363.0 | 95.5 | 10
71 | 391.3 | 10 | 373.7 | 95.5 | 10 | 380.5 | 97.2 | 10 | 374.0 | 95.6 | 10
78 | 404.4 | 10 | 387.5 | 95.8 | 10 | 392.3 | 97.0 | 10 | 382.4 | 94.5 | 10
85 | 413.5 | 10 | 394.2 | 95.3 | 10 | 398.4 | 96.3 | 10 | 391.5 | 94.7 | 10
EOS | 424.7 | 10 | 405.0 | 95.4 | 10 | 408.3 | 96.1 | 10 | 398.9 | 93.9 | 10
Female
1 | 106.3 | 10 | 107.7 | 101.4 | 10 | 106.4 | 100.1 | 10 | 106.4 | 100.2 | 10
8 | 134.1 | 10 | 133.7 | 99.7 | 10 | 135.3 | 100.9 | 10 | 130.3 | 97.2 | 10
15 | 154.4 | 10 | 152.6 | 98.8 | 10 | 156.7 | 101.5 | 10 | 151.0 | 97.8 | 10
22 | 169.5 | 10 | 169.2 | 99.8 | 10 | 172.9 | 102.0 | 10 | 166.0 | 97.9 | 10
29 | 188.9 | 10 | 183.7 | 97.2 | 10 | 188.6 | 99.9 | 10 | 177.8 | 94.1 | 10
36 | 195.6 | 10 | 196.2 | 100.3 | 10 | 199.2 | 101.8 | 10 | 186.0 | 95.1 | 10
43 | 207.0 | 10 | 203.0 | 98.1 | 10 | 205.4 | 99.2 | 10 | 193.8 | 93.7 | 10
50 | 214.5 | 10 | 210.2 | 98.0 | 10 | 215.6 | 100.5 | 10 | 203.0 | 94.6 | 10
57 | 220.4 | 10 | 216.1 | 98.0 | 10 | 221.8 | 100.6 | 10 | 208.6 | 94.6 | 10
64 | 224.4 | 10 | 222.1 | 98.9 | 10 | 227.9 | 101.5 | 10 | 212.6 | 94.7 | 10
71 | 229.8 | 10 | 225.6 | 98.2 | 10 | 232.8 | 101.3 | 10 | 218.1 | 94.9 | 10
78 | 237.8 | 10 | 226.2 | 95.1 | 10 | 237.8 | 100.0 | 10 | 224.3 | 94.3 | 10
85 | 240.7 | 10 | 233.8 | 97.2 | 10 | 244.7 | 101.7 | 10 | 228.9 | 95.1 | 10
EOS | 244.3 | 10 | 241.5 | 98.8 | 10 | 250.8 | 102.7 | 10 | 233.3 | 95.5 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 2

Growth Curves for Male and Female Rats in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride

Growth curves are shown for (A) males and (B) females.

At the highest Bmim-Cl exposure concentration (1 mg/mL), water consumption was 74%–86% (males) or 75%–87% (females) of the amount consumed by control groups over the course of the study (Table 11; Appendix E). Water consumption was not reduced to this extent in the low (0.1 mg/mL) or moderate (0.3 mg/mL) exposed groups. Drinking water concentrations of 0.1, 0.3, and 1 mg/mL resulted in estimated average doses of 9, 24, and 70 mg/kg/day for males and 11, 31, and 79 mg/kg/day for females, respectively.

Table 11 Summary of Water and 1-Butyl-3-Methylimidazolium Chloride Consumption of Male and Female Rats in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 0.1 mg/mL | 0.3 mg/mL | 1 mg/mL | 0.1 mg/mL | 0.3 mg/mL | 1 mg/mL
Male
1 | 24.5 | 28.3 | 22.4 | 20.1 | 20.1 | 48.0 | 142.3
3 | 24.9 | 28.1 | 24.5 | 21.3 | 12.1 | 31.8 | 93.4
6 | 25.2 | 24.1 | 22.0 | 18.7 | 7.7 | 21.0 | 60.1
9 | 23.6 | 23.5 | 23.6 | 18.1 | 6.6 | 19.7 | 51.2
13 | 22.7 | 22.1 | 20.6 | 17.7 | 5.6 | 15.5 | 45.2
Female
1 | 18.4 | 19.7 | 20.5 | 15.0 | 18.3 | 57.8 | 140.9
3 | 16.7 | 19.9 | 19.5 | 14.0 | 13.0 | 37.3 | 92.7
6 | 16.1 | 19.1 | 18.2 | 13.3 | 9.7 | 27.4 | 71.5
9 | 16.3 | 19.0 | 18.5 | 12.8 | 8.8 | 25.0 | 61.4
13 | 16.4 | 17.7 | 18.6 | 14.3 | 7.6 | 22.8 | 62.5

^a^ Mean g of water consumed/animal/day.

^b^ Mg of 1-butyl-3-methylimidazolium chloride consumed/kg body weight/day.

Although terminal mean body weights of Bmim-Cl-exposed rats were similar to those of control animals, two significant organ weight changes were observed. Absolute heart weights of males exposed to 1 mg/mL were significantly decreased (by 8%) compared to those of control rats (Table 12). Absolute lung weights of females exposed to 1 mg/mL were significantly decreased (by 15%) compared to those of control rats.

Table 12 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Rats in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride^a,b^

| 0 mg/mL | 0.1 mg/mL | 0.3 mg/mL | 1 mg/mL
n | 10 | 10 | 10 | 10
Male
Terminal Body Wt. (g) | 424.7 ± 8.7 | 405.0 ± 6.2 | 408.3 ± 13.5 | 398.9 ± 8.8
Heart
Absolute (g) | 1.56 ± 0.04* | 1.50 ± 0.02 | 1.45 ± 0.04 | 1.43 ± 0.03*
Relative (mg/g)^c^ | 3.66 ± 0.07 | 3.71 ± 0.04 | 3.55 ± 0.06 | 3.60 ± 0.07
Female
Terminal Body Wt. (g) | 244.3 ± 5.6 | 241.5 ± 4.5 | 250.8 ± 3.8 | 233.3 ± 3.5
Lung
Absolute (g) | 1.89 ± 0.10* | 1.72 ± 0.06 | 1.79 ± 0.09 | 1.60 ± 0.04*
Relative (mg/g) | 7.73 ± 0.36 | 7.13 ± 0.20 | 7.11 ± 0.31 | 6.86 ± 0.17

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

No changes in rat clinical chemistry parameters were attributable to Bmim-Cl exposure (Appendix E). At the end of the 3-month exposure period, there were mild (≤5%) but significant decreases, relative to control rats, in hematocrit, erythrocyte count, and hemoglobin concentrations in female rats exposed to 1 mg/mL (Table 13). Although there were no mean body weight changes observed, these changes in hematological parameters may have indicated a mild suppression in erythropoiesis due to chronic stress of exposure^103^; however, a mild direct effect due to exposure cannot be definitively ruled out. There were no exposure-related changes in the hematological parameters of the male rats (Appendix E).

Table 13 Summary of Select Hematology Data for Female Rats in the Three-month Drinking Water Study of 1Butyl-3-Methylimidazolium Chloride^a,b^

| 0 mg/mL | 0.1 mg/mL | 0.3 mg/mL | 1 mg/mL
n | 10 | 10 | 9 | 10
Hematocrit (%) | 46.5 ± 0.5** | 46.2 ± 0.3 | 46.7 ± 0.6 | 44.3 ± 0.4**
Erythrocytes (10^6^/μL) | 8.35 ± 0.10* | 8.29 ± 0.08 | 8.41 ± 0.08 | 8.00 ± 0.05*
Hemoglobin (g/dL) | 14.8 ± 0.1* | 14.8 ± 0.1 | 14.9 ± 0.2 | 14.3 ± 0.1*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

Estrous cycle length, number of cycles, and percentage of time spent in each respective stage of estrous were not affected by Bmim-Cl exposure. Assessment of the lengths of diestrus, proestrus, and estrus using the continuous-time Markov model did not reveal any Bmim-Cl-related differences in modeled stage lengths (Appendix E).

No exposure-related gross or histopathological changes were observed in male or female rats exposed to Bmim-Cl (Appendix E).

#### 1-Butyl-1-Methylpyrrolidinium Chloride (Bmpy-Cl)

Male and female rats were exposed to different concentrations of Bmpy-Cl in drinking water due to sex differences observed in the 2-week studies. Male rats were exposed to 0, 0.3, 1, or 3 mg/mL Bmpy-Cl, and female rats were exposed to 0, 1, 3, or 6 mg/mL Bmpy-Cl. All rats survived to the end of the 3-month exposure period (Table 14) and no exposure-related clinical observations were noted (Appendix E). Mean body weights of male rats were within 10% of the control group mean body weights throughout the study, although a 7% decrease in the terminal mean body weight of the 3 mg/mL group was significantly different from the control group (Table 14; Figure 3; Appendix E). Mean body weights of female rats in the 6 mg/mL group were consistently lower than those of control rats throughout the study, and the terminal mean body weight was significantly decreased (12%) relative to the control group. In females exposed to 1 or 3 mg/mL, mean body weights were similar to control animal values throughout the study.

Table 14 Summary of Survival and Mean Body Weights of Male and Female Rats in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride

Study Day^a^ | 0 mg/mL | | 0.3 mg/mL | | | 1 mg/mL | | | 3 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 157.7 | 10 | 159.5 | 101.1 | 10 | 157.0 | 99.5 | 10 | 158.0 | 100.2 | 10
8 | 206.3 | 10 | 204.7 | 99.2 | 10 | 201.7 | 97.8 | 10 | 195.5 | 94.7 | 10
15 | 254.0 | 10 | 248.3 | 97.8 | 10 | 243.6 | 95.9 | 10 | 236.9 | 93.3 | 10
22 | 288.0 | 10 | 282.4 | 98.1 | 10 | 276.8 | 96.1 | 10 | 267.3 | 92.8 | 10
29 | 313.2 | 10 | 305.4 | 97.5 | 10 | 302.0 | 96.4 | 10 | 290.7 | 92.8 | 10
36 | 332.5 | 10 | 323.1 | 97.2 | 10 | 321.3 | 96.6 | 10 | 308.5 | 92.8 | 10
43 | 350.4 | 10 | 341.1 | 97.4 | 10 | 338.1 | 96.5 | 10 | 326.6 | 93.2 | 10
50 | 366.0 | 10 | 355.9 | 97.2 | 10 | 351.7 | 96.1 | 10 | 341.1 | 93.2 | 10
57 | 375.1 | 10 | 365.0 | 97.3 | 10 | 362.1 | 96.5 | 10 | 354.0 | 94.4 | 10
64 | 387.2 | 10 | 378.2 | 97.7 | 10 | 372.9 | 96.3 | 10 | 364.7 | 94.2 | 10
71 | 398.1 | 10 | 387.8 | 97.4 | 10 | 381.8 | 95.9 | 10 | 372.2 | 93.5 | 10
78 | 409.4 | 10 | 397.0 | 97.0 | 10 | 391.0 | 95.5 | 10 | 382.6 | 93.5 | 10
85 | 418.9 | 10 | 408.3 | 97.5 | 10 | 399.7 | 95.4 | 10 | 391.9 | 93.6 | 10
EOS | 429.6 | 10 | 417.0 | 97.1 | 10 | 412.6 | 96.1 | 10 | 399.0 | 92.9 | 10
Study Day | 0 mg/mL | | 1 mg/mL | | | 3 mg/mL | | | 6 mg/mL
Study Day | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Female
1 | 104.2 | 10 | 104.8 | 100.6 | 10 | 106.9 | 102.6 | 10 | 105.6 | 101.4 | 10
8 | 135.0 | 10 | 134.6 | 99.7 | 10 | 132.2 | 97.9 | 10 | 99.2 | 73.5 | 10
15 | 156.5 | 10 | 152.9 | 97.7 | 10 | 153.1 | 97.9 | 10 | 124.3 | 79.5 | 10
22 | 176.0 | 10 | 171.2 | 97.3 | 10 | 170.5 | 96.9 | 10 | 141.4 | 80.3 | 10
29 | 189.1 | 10 | 188.2 | 99.6 | 10 | 184.1 | 97.4 | 10 | 156.1 | 82.5 | 10
36 | 197.0 | 10 | 198.8 | 100.9 | 10 | 195.5 | 99.2 | 10 | 167.6 | 85.1 | 10
43 | 207.1 | 10 | 206.2 | 99.5 | 10 | 203.8 | 98.4 | 10 | 176.2 | 85.1 | 10
50 | 217.2 | 10 | 215.9 | 99.4 | 10 | 215.5 | 99.2 | 10 | 186.5 | 85.8 | 10
57 | 223.4 | 10 | 219.7 | 98.3 | 10 | 219.2 | 98.1 | 10 | 192.8 | 86.3 | 10
64 | 230.4 | 10 | 225.0 | 97.7 | 10 | 226.4 | 98.3 | 10 | 199.5 | 86.6 | 10
71 | 232.9 | 10 | 230.9 | 99.1 | 10 | 230.2 | 98.8 | 10 | 208.1 | 89.3 | 10
78 | 237.3 | 10 | 234.5 | 98.8 | 10 | 235.5 | 99.3 | 10 | 210.7 | 88.8 | 10
85 | 243.6 | 10 | 243.4 | 99.9 | 10 | 244.8 | 100.5 | 10 | 219.0 | 89.9 | 10
EOS | 250.1 | 10 | 249.4 | 99.7 | 10 | 251.6 | 100.6 | 10 | 220.4 | 88.1 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 3

Growth Curves for Male and Female Rats in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride

Growth curves are shown for (A) males and (B) females.

In general, water consumption by both male and female rats exposed to Bmpy-Cl decreased in an exposure concentration-dependent manner. At any given concentration, however, female rats consumed less water than male rats. Water consumption by male rats exposed to 3 mg/mL Bmpy-Cl, was 75%–85% of control animals (Table 15), whereas water consumption by female rats exposed to 3 mg/mL was 68%–76% of control animals. In female rats exposed to 6 mg/mL, water consumption was reduced even further to 26%–63% of consumption by control animals. The lowest water consumption value of 26% by females was observed during week 1 of the study and was potentially due to the poor palatability of the dose formulation. Drinking water concentrations of 0.3, 1, and 3 mg/mL resulted in estimated average doses of 26, 74, and 201 mg/kg/day, respectively, for males, and drinking water concentrations of 1, 3, and 6 mg/mL resulted in estimated average doses of 89, 222, and 376 mg/kg/day, respectively, for females.

Table 15 Summary of Water and 1-Butyl-1-Methylpyrrolidinium Chloride Consumption of Male and Female Rats in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL
Male
1 | 23.7 | 24.7 | 21.7 | 18.3 | 46.5 | 138.2 | 347.6
3 | 25.9 | 26.2 | 22.3 | 19.5 | 31.7 | 91.5 | 246.9
6 | 25.0 | 25.3 | 21.7 | 19.6 | 23.5 | 67.5 | 190.6
9 | 22.9 | 24.7 | 21.1 | 18.6 | 20.3 | 58.3 | 157.6
13 | 23.6 | 25.2 | 20.9 | 19.0 | 18.5 | 52.3 | 145.4
| 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
Female
1 | 17.6 | 15.2 | 13.3 | 4.5 | 145.1 | 373.2 | 255.7
3 | 17.9 | 15.9 | 13.0 | 9.4 | 104.0 | 254.7 | 453.7
6 | 18.7 | 17.8 | 13.7 | 11.3 | 89.5 | 210.3 | 404.6
9 | 19.5 | 16.0 | 13.6 | 11.3 | 72.8 | 186.1 | 351.7
13 | 19.3 | 18.0 | 14.5 | 11.5 | 74.0 | 177.7 | 315.1

^a^ Mean g of water consumed/animal/day.

^b^ Mg of 1-butyl-1-methylpyrrolidinium chloride consumed/kg body weight/day.

Significant organ weight changes were observed only in female rats exposed to Bmpy-Cl (Table 16; Appendix E). In female rats exposed to 6 mg/mL, which had significant terminal mean body weight decreases, absolute mean liver weights were significantly decreased by 20% compared to control rats. Relative mean liver weights were also significantly decreased in this group. Furthermore, relative right kidney and heart weights were significantly increased in the 6 mg/mL females compared to control rats; however, these changes were considered secondary effects of decreased body weight and/or water consumption (Appendix E). Despite not experiencing significant decreases in body weights, female rats in the 1 and 3 mg/mL groups had significant decreases in relative liver weights (Table 16).

Table 16 Summary of Liver Weights and Liver-Weight-to-Body-Weight Ratios for Female Rats in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride^a,b^

| 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
n | 10 | 10 | 10 | 10
Terminal Body Wt. (g) | 250.1 ± 3.8** | 249.4 ± 5.1 | 251.6 ± 6.5 | 220.4 ± 3.9**
Liver
Absolute (g) | 9.11 ± 0.26** | 8.46 ± 0.36 | 8.49 ± 0.33 | 7.28 ± 0.21**
Relative (mg/g)^c^ | 36.41 ± 0.91** | 33.78 ± 0.88* | 33.69 ± 0.75* | 33.00 ± 0.57**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

No changes in rat hematology parameters were attributable to Bmpy-Cl exposure. Female rats in the 6 mg/mL group had a significant decrease in alanine aminotransferase activity compared to control rats (Appendix E). Given that the decrease was mild, only present in the highest exposed group, and not observed in male rats, these changes were considered related to biological variability rather than Bmpy-Cl exposure.

Estrous cycle length, number of cycles, and percentage of time spent in each respective stage of estrous were not affected by Bmpy-Cl exposure. Assessment of the lengths of diestrus, proestrus, and estrus using the continuous-time Markov model did not reveal any Bmpy-Cl-related differences in modeled stage lengths. Four females exposed to 6 mg/mL were not cycling, which likely resulted from nonspecific stress, as indicated by the consistently lower mean body weights of these rats compared to control rats (Table 14; Figure 3; Appendix E).

No exposure-related gross or histopathological changes were observed in male or female rats exposed to Bmpy-Cl (Appendix E).

#### N-Butylpyridinium Chloride (NBuPy-Cl)

Male and female rats were exposed to NBuPy-Cl at concentrations of 0, 0.3, 1, or 3 mg/mL in drinking water. Apart from one death (considered unrelated to exposure) of a male rat exposed to 3 mg/mL on study day 6, all rats survived to the end of the 3-month exposure period (Table 17). No exposure-related clinical observations were noted (Appendix E). Although most body weight changes during the study were within 10% of control animals, significantly decreased terminal mean body weights (approximately 89%–95% of control animals) were noted in the 1 mg/mL NBuPy-Cl-exposed male rats and the 3 mg/mL NBuPy-Cl-exposed male and female rats (Table 17; Figure 4; Appendix E). These were interpreted as lower body weight gain, as opposed to body weight loss, during the exposure period.

Table 17 Summary of Survival and Mean Body Weights of Male and Female Rats in the Three-month Drinking Water Study of N-Butylpyridinium Chloride

Study Day^a^ | 0 mg/mL | | 0.3 mg/mL | | | 1 mg/mL | | | 3 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 157.2 | 10 | 156.1 | 99.3 | 10 | 155.4 | 98.9 | 10 | 156.9 | 99.8 | 10
8 | 206.3 | 10 | 203.9 | 98.9 | 10 | 199.4 | 96.7 | 10 | 185.4 | 89.9 | 9
15 | 250.2 | 10 | 249.0 | 99.5 | 10 | 239.7 | 95.8 | 10 | 224.7 | 89.8 | 9
22 | 285.0 | 10 | 284.3 | 99.7 | 10 | 272.3 | 95.5 | 10 | 257.2 | 90.3 | 9
29 | 309.0 | 10 | 307.7 | 99.6 | 10 | 293.0 | 94.8 | 10 | 278.5 | 90.1 | 9
36 | 336.9 | 10 | 332.7 | 98.7 | 10 | 314.1 | 93.2 | 10 | 299.9 | 89.0 | 9
43 | 352.2 | 10 | 348.6 | 99.0 | 10 | 329.7 | 93.6 | 10 | 315.6 | 89.6 | 9
50 | 365.6 | 10 | 361.4 | 98.8 | 10 | 343.4 | 93.9 | 10 | 330.2 | 90.3 | 9
57 | 380.7 | 10 | 373.5 | 98.1 | 10 | 353.7 | 92.9 | 10 | 339.1 | 89.1 | 9
64 | 390.0 | 10 | 380.4 | 97.5 | 10 | 364.0 | 93.3 | 10 | 346.3 | 88.8 | 9
71 | 401.7 | 10 | 396.3 | 98.6 | 10 | 381.7 | 95.0 | 10 | 357.9 | 89.1 | 9
78 | 409.9 | 10 | 405.2 | 98.8 | 10 | 387.9 | 94.6 | 10 | 363.9 | 88.8 | 9
85 | 417.2 | 10 | 413.8 | 99.2 | 10 | 396.5 | 95.0 | 10 | 371.6 | 89.1 | 9
EOS | 426.8 | 10 | 420.7 | 98.6 | 10 | 403.4 | 94.5 | 10 | 379.1 | 88.8 | 9
Female
1 | 108.2 | 10 | 105.7 | 97.7 | 10 | 105.5 | 97.5 | 10 | 106.8 | 98.7 | 10
8 | 137.1 | 10 | 132.7 | 96.8 | 10 | 134.4 | 98.0 | 10 | 121.0 | 88.2 | 10
15 | 158.2 | 10 | 151.3 | 95.6 | 10 | 154.6 | 97.7 | 10 | 139.7 | 88.3 | 10
22 | 178.1 | 10 | 168.6 | 94.6 | 10 | 170.2 | 95.6 | 10 | 155.3 | 87.2 | 10
29 | 189.7 | 10 | 181.5 | 95.6 | 10 | 181.8 | 95.8 | 10 | 165.1 | 87.0 | 10
36 | 201.4 | 10 | 193.6 | 96.1 | 10 | 192.8 | 95.7 | 10 | 175.8 | 87.3 | 10
43 | 210.7 | 10 | 201.9 | 95.8 | 10 | 201.5 | 95.6 | 10 | 184.0 | 87.3 | 10
50 | 218.9 | 10 | 212.9 | 97.3 | 10 | 208.2 | 95.1 | 10 | 192.1 | 87.7 | 10
57 | 225.9 | 10 | 219.4 | 97.1 | 10 | 216.8 | 96.0 | 10 | 199.3 | 88.2 | 10
64 | 229.7 | 10 | 223.3 | 97.2 | 10 | 221.7 | 96.5 | 10 | 204.3 | 89.0 | 10
71 | 234.6 | 10 | 228.0 | 97.2 | 10 | 227.4 | 96.9 | 10 | 208.4 | 88.8 | 10
78 | 238.2 | 10 | 233.2 | 97.9 | 10 | 228.9 | 96.1 | 10 | 211.7 | 88.9 | 10
85 | 244.5 | 10 | 237.9 | 97.3 | 10 | 238.5 | 97.6 | 10 | 217.0 | 88.7 | 10
EOS | 247.6 | 10 | 240.3 | 97.1 | 10 | 242.0 | 97.7 | 10 | 221.8 | 89.6 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 4

Growth Curves for Male and Female Rats in the Three-month Drinking Water Study of N-Butylpyridinium Chloride

Growth curves are shown for (A) males and (B) females.

Water consumption was lower relative to control groups for males exposed to ≥0.3 mg/mL NBuPy-Cl or females exposed to ≥1 mg/mL and decreased with increasing exposure concentration (Table 18). At the highest exposure concentration of 3 mg/mL, water consumption by male rats was 47%–69% of the control group (Appendix E). Female rats exposed to the highest exposure concentration of 3 mg/mL had mean water consumption ranging from 47% to 63% of the control group (Table 18). The lowest water consumption value of 47% of the control group for both males and females exposed to 3 mg/mL was observed on week 1 of the study and was potentially due to the formulation’s poor palatability. Drinking water concentrations of 0.3, 1, and 3 mg/mL resulted in estimated average doses of 23, 73, and 171 mg/kg/day, respectively, for males and 30, 83, and 184 mg/kg/day, respectively, for females.

Table 18 Summary of Water and N-Butylpyridinium Chloride Consumption of Male and Female Rats in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL
Male
1 | 26.8 | 24.3 | 21.8 | 12.5 | 46.7 | 140.3 | 238.9
3 | 26.7 | 24.3 | 21.9 | 16.9 | 29.3 | 91.4 | 225.6
6 | 25.8 | 24.2 | 20.0 | 16.6 | 21.8 | 63.7 | 166.0
9 | 24.3 | 22.0 | 20.5 | 15.8 | 17.7 | 58.0 | 139.8
13 | 24.0 | 21.8 | 20.6 | 15.8 | 15.8 | 52.0 | 127.6
Female
1 | 17.5 | 18.2 | 15.2 | 8.2 | 51.7 | 144.1 | 230.3
3 | 17.2 | 17.2 | 14.1 | 10.2 | 34.1 | 91.2 | 219.1
6 | 17.2 | 18.4 | 15.0 | 10.8 | 28.5 | 77.8 | 184.3
9 | 18.7 | 18.4 | 15.4 | 10.5 | 25.2 | 71.0 | 158.0
13 | 19.7 | 20.6 | 15.8 | 11.1 | 26.0 | 66.2 | 153.5

^a^ Mean g of water consumed/animal/day.

^b^ Mg of n-butylpyridinium chloride consumed/kg body weight/day.

Significant organ weight changes were observed in male and female rats exposed to NBuPy-Cl, but all changes were considered secondary effects of decreased body weight and/or water consumption (Appendix E). Alongside a significant decrease in terminal mean body weight, male rats in the 3 mg/mL group had significantly increased relative heart, right kidney, and liver weights. Females in the 3 mg/mL group similarly had a significant decrease in terminal mean body weight accompanied by significantly increased relative heart and right kidney weights. These females also had significantly decreased absolute liver weights. Males in the 1 mg/mL group had a smaller (approximately 5%) significant decrease in terminal mean body weight accompanied by significantly increased relative right kidney and liver weights. Males in the 0.3 mg/mL group, which did not have a significantly different terminal mean body weight, had significantly increased relative right kidney weights. This change was very small, however, and was not considered toxicologically relevant.

At the end of the 3-month exposure period, the 1 and 3 mg/mL male rats had a significant increase in urea nitrogen concentration (Appendix E). This increase was mild and not observed in females; therefore, the change was considered unrelated to NBuPy-Cl exposure and might have indicated mild dehydration due to lower water consumption. There were no changes in rat hematology parameters attributable to NBuPy-Cl administration in drinking water (Appendix E).

Estrous cycle length, number of cycles, and percentage of time spent in each respective stage of estrous were not affected by NBuPy-Cl exposure. Assessment of the lengths of diestrus, proestrus, and estrus using the continuous-time Markov model did not reveal any NBuPy-Cl-related differences in modeled stage lengths (Appendix E).

No exposure-related gross or histopathological changes were observed in male or female rats exposed to NBuPy-Cl (Appendix E).

### Mice

#### 1-Ethyl-3-Methylimidazolium Chloride (Emim-Cl)

Male and female mice were exposed to Emim-Cl at concentrations of 0, 3, 10, and 30 mg/mL in drinking water. All mice survived to the end of the 3-month exposure period (Table 19), and no exposure-related clinical observations were noted (Appendix E). Male mice exposed to 10 mg/mL and both male and female mice exposed to 30 mg/mL had significantly decreased terminal mean body weights, relative to control mice, which was interpreted as lower weight gain over the course of the study (Table 19; Figure 5; Appendix E). At the 30 mg/mL exposure concentration, male and female terminal mean body weights were 71% and 79%, respectively, of the control groups. At 10 mg/mL exposure concentration, male terminal body weights were 93% of the control group. Male and female mice exposed to 3 mg/mL and female mice exposed to 10 mg/mL maintained mean body weights within 10% of the control groups, and these differences were not significant (Appendix E).

Table 19 Summary of Survival and Mean Body Weights of Male and Female Mice in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride

Study Day^a^ | 0 mg/mL | | 3 mg/mL | | | 10 mg/mL | | | 30 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 23.2 | 10 | 23.1 | 99.9 | 10 | 23.1 | 99.8 | 10 | 23.1 | 99.7 | 10
8 | 24.5 | 10 | 24.5 | 100.0 | 10 | 24.1 | 98.3 | 10 | 21.8 | 88.8 | 10
15 | 25.6 | 10 | 25.9 | 101.3 | 10 | 25.5 | 99.8 | 10 | 22.7 | 88.8 | 10
22 | 26.9 | 10 | 27.2 | 101.3 | 10 | 26.6 | 99.1 | 10 | 23.6 | 88.0 | 10
29 | 28.0 | 10 | 28.6 | 102.1 | 10 | 27.9 | 99.9 | 10 | 24.3 | 86.8 | 10
36 | 28.6 | 10 | 29.6 | 103.6 | 10 | 28.4 | 99.4 | 10 | 24.5 | 85.7 | 10
43 | 30.4 | 10 | 31.4 | 103.3 | 10 | 29.7 | 98.0 | 10 | 22.3 | 73.5 | 10
50 | 31.6 | 10 | 32.5 | 102.8 | 10 | 30.8 | 97.6 | 10 | 24.0 | 75.8 | 10
57 | 33.2 | 10 | 34.0 | 102.3 | 10 | 32.2 | 96.8 | 10 | 25.2 | 75.8 | 10
64 | 34.3 | 10 | 35.1 | 102.2 | 10 | 32.9 | 95.8 | 10 | 26.3 | 76.7 | 10
71 | 36.0 | 10 | 36.7 | 101.9 | 10 | 34.2 | 95.0 | 10 | 26.9 | 74.9 | 10
78 | 37.2 | 10 | 37.9 | 101.9 | 10 | 34.6 | 93.2 | 10 | 27.1 | 73.0 | 10
85 | 38.6 | 10 | 39.2 | 101.4 | 10 | 36.1 | 93.4 | 10 | 27.7 | 71.7 | 10
EOS | 38.9 | 10 | 39.1 | 100.6 | 10 | 36.2 | 93.0 | 10 | 27.8 | 71.3 | 10
Female
1 | 17.4 | 10 | 17.3 | 99.8 | 10 | 16.9 | 97.5 | 10 | 17.0 | 97.8 | 10
8 | 18.5 | 10 | 18.4 | 99.4 | 10 | 18.6 | 100.4 | 10 | 16.4 | 88.7 | 10
15 | 19.5 | 10 | 19.3 | 99.2 | 10 | 19.5 | 100.0 | 10 | 17.3 | 88.5 | 10
22 | 20.4 | 10 | 20.3 | 99.1 | 10 | 20.7 | 101.3 | 10 | 18.5 | 90.3 | 10
29 | 21.7 | 10 | 21.3 | 98.1 | 10 | 21.6 | 99.7 | 10 | 19.3 | 89.0 | 10
36 | 22.3 | 10 | 21.8 | 97.8 | 10 | 22.0 | 98.9 | 10 | 20.0 | 89.8 | 10
43 | 23.7 | 10 | 23.0 | 97.2 | 10 | 23.2 | 98.0 | 10 | 20.8 | 87.6 | 10
50 | 24.5 | 10 | 23.0 | 93.9 | 10 | 23.4 | 95.5 | 10 | 21.2 | 86.6 | 10
57 | 25.4 | 10 | 24.3 | 95.7 | 10 | 25.0 | 98.7 | 10 | 21.8 | 86.1 | 10
64 | 26.6 | 10 | 24.3 | 91.4 | 10 | 25.4 | 95.4 | 10 | 22.2 | 83.4 | 10
71 | 28.9 | 10 | 26.4 | 91.3 | 10 | 26.4 | 91.3 | 10 | 22.9 | 79.3 | 10
78 | 28.5 | 10 | 25.6 | 89.9 | 10 | 26.2 | 92.2 | 10 | 22.5 | 79.1 | 10
85 | 28.8 | 10 | 26.3 | 91.2 | 10 | 27.0 | 93.6 | 10 | 23.0 | 79.7 | 10
EOS | 29.2 | 10 | 26.6 | 91.0 | 10 | 27.8 | 95.2 | 10 | 23.0 | 78.8 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 5

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride

Growth curves are shown for (A) males and (B) females.

In general, water consumption decreased in an exposure concentration-dependent manner for both male and female mice exposed to Emim-Cl (Table 20; Appendix E). In the highest exposed group (30 mg/mL), mean water consumption ranged from 44% to 66% of control animals for males and from 43% to 87% of control animals for females. Drinking water concentrations of 3, 10, and 30 mg/mL resulted in estimated average doses of 341, 1,039, and 2,283 mg/kg/day, respectively, for males and 383, 1,198, and 2,457 mg/kg/day, respectively, for females.

Table 20 Summary of Water and 1-Ethyl-3-Methylimidazolium Chloride Consumption of Male and Female Mice in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 3 mg/mL | 10 mg/mL | 30 mg/mL | 3 mg/mL | 10 mg/mL | 30 mg/mL
Male
2^c^ | 3.4 | 3.5 | 3.2 | 1.8 | 428.0 | 1,327.3 | 2,479.3
3 | 3.5 | 3.6 | 3.2 | 1.8 | 416.7 | 1,253.4 | 2,377.8
6 | 3.5 | 3.6 | 3.1 | 2.1 | 364.4 | 1,090.8 | 2,570.4
9 | 3.3 | 3.5 | 2.9 | 2.0 | 308.9 | 901.2 | 2,381.0
13 | 3.3 | 3.4 | 3.3 | 1.9 | 260.5 | 914.9 | 2,058.5
Female
1 | 2.6 | 2.7 | 2.8 | 1.2 | 467.4 | 1,654.8 | 2,120.1
3 | 2.8 | 2.7 | 2.4 | 1.4 | 418.8 | 1,230.8 | 2,433.4
6 | 3.7 | 2.9 | 2.6 | 1.6 | 399.6 | 1,181.8 | 2,402.4
9 | 3.0 | 3.0 | 2.7 | 1.8 | 371.0 | 1,078.3 | 2,473.7
13 | 3.0 | 2.8 | 2.8 | 2.0 | 319.8 | 1,037.8 | 2,613.2

^a^ Mean g of water consumed/animal/day.

^b^ Mg of 1-ethyl-3-methylimidazolium chloride consumed/kg body weight/day.

^c^ Week 1 data unavailable for male mice.

Terminal mean body weights of mice exposed to Emim-Cl were significantly decreased at the highest exposure concentration of 30 mg/mL (Appendix E). Accordingly, significant organ weight changes were observed for both male and female mice exposed to 30 mg/mL; however, these were considered secondary effects of decreased body weight and/or water consumption (Appendix E). Males exposed to 30 mg/mL had significantly decreased absolute right kidney and liver weights (by 19% and 23%, respectively) compared to the control group. These males also had significantly increased relative heart, right kidney, liver, lung, and right testis weights. Females exposed to 30 mg/mL had significantly decreased absolute heart and liver weights (by 13% and 20%, respectively), as well as significantly increased relative right kidney weights, compared to control animals. Males in the 10 mg/mL group had a smaller (7%) significant decrease in terminal mean body weights compared to control animals, accompanied by a significant increase in relative right testis weight. Again, this organ weight change was considered a secondary effect of decreased body weight and/or water consumption.

At the end of the 3-month exposure period, there was a mild increase in the erythron of the 30 mg/mL male mice (Table 21). These changes included significant increases in the manual hematocrit, erythrocyte count, and reticulocyte count compared to control animals and were consistent with mild hemoconcentration due to lower water consumption. Similarly, a significant increase in erythrocyte counts and reticulocyte counts were observed in the 30 mg/mL female mice.

Table 21 Summary of Select Hematology Data for Male and Female Mice in the Three-month Drinking Water Study of 1Ethyl-3-Methylimidazolium Chloride^a,b^

| 0 mg/mL | 3 mg/mL | 10 mg/mL | 30 mg/mL
n | 10 | 10 | 10 | 10
Male
Manual Hematocrit (%) | 48.7 ± 0.3* | 49.3 ± 0.4 | 48.8 ± 0.4 | 50.2 ± 0.4*
Erythrocytes (10^6^/μL) | 11.05 ± 0.09** | 11.13 ± 0.14 | 11.07 ± 0.08 | 11.62 ± 0.11**
Reticulocytes (10^3^/μL) | 241.9 ± 8.0** | 233.2 ± 7.4 | 253.7 ± 7.4 | 273.8 ± 3.7**
Female
Erythrocytes (10^6^/μL) | 10.84 ± 0.20** | 11.06 ± 0.17 | 11.45 ± 0.29 | 11.99 ± 0.28**
Reticulocytes (10^3^/μL) | 231.5 ± 17.4* | 270.9 ± 14.7 | 291.3 ± 18.8* | 280.7 ± 11.5

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

Emim-Cl exposure in female mice did not affect estrous cycle length, number of cycles, and percentage of time spent in each respective stage of estrous. Assessment of the lengths of diestrus, proestrus, and estrus using the continuous-time Markov model did not reveal any Emim-Cl-related differences in modeled stage lengths (Appendix E).

Limited histopathological changes were observed in male and female mice exposed to Emim-Cl (Table 22). There were significant increases in the incidences of chronic progressive nephropathy and renal tubule cytoplasmic alteration in males exposed to 30 mg/mL relative to the control group. There was also a positive trend in the incidences of renal infarct in male mice. Similar histological findings were not observed in the kidneys of female mice. However, there was a significant increase in the incidence of adrenal cortex persistent X-zone in females exposed to 30 mg/mL compared to the control group. The morphological features of the lesions discussed in this section are presented in the Histopathological Descriptions of Mice section.

Table 22 Incidences of Nonneoplastic Lesions of the Kidney and Adrenal Gland in Male and Female Mice in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride

| 0 mg/mL | 3 mg/mL | 10 mg/mL | 30 mg/mL
n ^a^ | 10 | 10 | 10 | 10
Male
Kidney
Infarct^b^ | 0* | 0 | 0 | 2 (1.0)^c^
Nephropathy, chronic progressive | 1** (1.0) | 1 (1.0) | 2 (1.0) | 8** (1.0)
Renal tubule, cytoplasmic alteration | 0** | 0 | 0 | 9** (1.7)
Female
Adrenal Gland
Adrenal cortex, X-zone, persistent | 0** | 1 | 0 | 8**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals; 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

#### 1-Butyl-3-Methylimidazolium Chloride (Bmim-Cl)

Male and female mice were exposed to Bmim-Cl at concentrations of 0, 0.3, 1, and 3 mg/mL in drinking water. All mice survived to the end of the 3-month exposure period (Table 23) and no exposure-related clinical observations were noted (Appendix E). Male mice exposed to 3 mg/mL had a significantly decreased terminal mean body weight (77% of the control group), which was interpreted as lower weight gain over the course of the study (Table 23; Figure 6; Appendix E). Female terminal mean body weight at this exposure concentration was significantly decreased at 91% of the control group. Mice exposed to 0.3 or 1 mg/mL maintained body weights within 10% of the control groups.

Table 23 Summary of Survival and Mean Body Weights of Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride

Study Day^a^ | 0 mg/mL | | 0.3 mg/mL | | | 1 mg/mL | | | 3 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 21.9 | 10 | 21.7 | 99.2 | 10 | 21.8 | 99.4 | 10 | 21.7 | 99.0 | 10
8 | 23.9 | 10 | 23.7 | 99.2 | 10 | 23.3 | 97.7 | 10 | 22.6 | 94.7 | 10
15 | 25.5 | 10 | 25.6 | 100.6 | 10 | 25.1 | 98.6 | 10 | 23.8 | 93.4 | 10
22 | 26.9 | 10 | 27.1 | 100.6 | 10 | 26.4 | 98.1 | 10 | 24.3 | 90.3 | 10
29 | 28.0 | 10 | 28.0 | 100.0 | 10 | 27.1 | 96.9 | 10 | 25.3 | 90.4 | 10
36 | 29.6 | 10 | 29.2 | 98.9 | 10 | 28.2 | 95.4 | 10 | 25.4 | 85.9 | 10
43 | 30.6 | 10 | 30.5 | 99.5 | 10 | 29.4 | 95.9 | 10 | 25.8 | 84.3 | 10
50 | 32.0 | 10 | 31.5 | 98.7 | 10 | 30.4 | 95.2 | 10 | 26.7 | 83.5 | 10
57 | 33.0 | 10 | 32.8 | 99.4 | 10 | 31.2 | 94.7 | 10 | 27.2 | 82.5 | 10
64 | 34.7 | 10 | 34.5 | 99.4 | 10 | 32.8 | 94.5 | 10 | 28.0 | 80.8 | 10
71 | 36.3 | 10 | 35.6 | 98.0 | 10 | 34.0 | 93.8 | 10 | 28.5 | 78.7 | 10
78 | 37.2 | 10 | 36.6 | 98.2 | 10 | 34.6 | 92.9 | 10 | 29.2 | 78.4 | 10
85 | 38.0 | 10 | 37.7 | 99.2 | 10 | 35.9 | 94.3 | 10 | 29.7 | 78.1 | 10
EOS | 38.8 | 10 | 38.6 | 99.6 | 10 | 36.5 | 94.0 | 10 | 29.7 | 76.6 | 10
Female
1 | 17.2 | 10 | 17.0 | 99.2 | 10 | 16.7 | 97.3 | 10 | 16.9 | 98.2 | 10
8 | 18.3 | 10 | 17.8 | 97.6 | 10 | 17.9 | 98.2 | 10 | 17.7 | 97.0 | 10
15 | 19.6 | 10 | 18.9 | 96.4 | 10 | 19.3 | 98.7 | 10 | 18.3 | 93.5 | 10
22 | 20.3 | 10 | 19.7 | 96.7 | 10 | 20.3 | 99.6 | 10 | 19.1 | 94.1 | 10
29 | 21.5 | 10 | 20.7 | 96.4 | 10 | 21.1 | 98.4 | 10 | 19.7 | 91.7 | 10
36 | 22.2 | 10 | 22.0 | 99.1 | 10 | 22.2 | 99.7 | 10 | 20.7 | 93.1 | 10
43 | 23.2 | 10 | 22.5 | 97.2 | 10 | 22.8 | 98.5 | 10 | 21.6 | 93.4 | 10
50 | 23.6 | 10 | 23.1 | 97.7 | 10 | 23.3 | 98.7 | 10 | 22.0 | 93.0 | 10
57 | 24.4 | 10 | 23.8 | 97.4 | 10 | 23.9 | 98.0 | 10 | 22.7 | 93.0 | 10
64 | 24.7 | 10 | 24.6 | 99.5 | 10 | 24.6 | 99.6 | 10 | 23.3 | 94.3 | 10
71 | 26.5 | 10 | 25.6 | 96.6 | 10 | 25.5 | 96.0 | 10 | 23.4 | 88.3 | 10
78 | 26.0 | 10 | 26.4 | 101.3 | 10 | 25.9 | 99.4 | 10 | 23.4 | 90.0 | 10
85 | 26.5 | 10 | 25.7 | 97.3 | 10 | 25.9 | 97.8 | 10 | 23.6 | 89.2 | 10
EOS | 26.8 | 10 | 26.3 | 97.9 | 10 | 26.3 | 98.1 | 10 | 24.4 | 91.0 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 6

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride

Growth curves are shown for (A) males and (B) females.

In general, water consumption decreased in an exposure concentration-dependent manner for both male and female mice exposed to Bmim-Cl (Table 24; Appendix E). At the highest exposure concentration of 3 mg/mL, water consumption by male mice was 56%–77% of the control group. In female mice exposed to 3 mg/mL, water consumption was 47%–69% of the control group. Drinking water concentrations of 0.3, 1, and 3 mg/mL resulted in estimated average doses of 37, 116, and 262 mg/kg/day, respectively, for males and 39, 125, and 270 mg/kg/day, respectively, for females.

Table 24 Summary of Water and 1-Butyl-3-Methylimidazolium Chloride Consumption of Male and Female Mice in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL
Male
2^c^ | 3.7 | 3.8 | 3.5 | 2.7 | 48.1 | 150.1 | 358.1
3 | 3.7 | 4.0 | 3.7 | 2.6 | 46.8 | 147.4 | 327.9
6 | 3.6 | 3.6 | 3.2 | 2.0 | 36.9 | 113.5 | 236.2
9 | 3.5 | 3.6 | 3.4 | 2.1 | 33.0 | 108.9 | 231.4
13 | 3.5 | 3.8 | 3.5 | 2.7 | 30.2 | 97.6 | 272.6
Female
1 | 2.9 | 2.4 | 2.6 | 1.8 | 42.3 | 155.6 | 320.3
3 | 3.8 | 2.6 | 2.7 | 1.8 | 41.3 | 139.7 | 294.9
6 | 3.0 | 3.0 | 2.9 | 1.9 | 40.9 | 130.9 | 275.8
9 | 2.9 | 2.9 | 2.9 | 2.0 | 36.6 | 121.1 | 264.3
13 | 3.1 | 2.8 | 2.8 | 1.9 | 32.6 | 108.2 | 241.6

^a^ Mean g of water consumed/animal/day.

^b^ Mg of 1-butyl-3-methylimidazolium chloride consumed/kg body weight/day.

^c^ Week 1 data unavailable for male mice.

Terminal mean body weight was significantly decreased in mice exposed to 3 mg/mL Bmim-Cl (Appendix E). Significant organ weight changes, considered secondary effects of decreased body weight and/or water consumption, were observed for both male and female mice exposed to this concentration. In males, absolute right kidney and liver weights were significantly decreased compared to the control group. Relative heart, right kidney, liver, lung, and right testis weights were significantly increased compared to the control group. Absolute lung weights were also significantly decreased in 3 mg/mL females compared to the control group. Additionally, relative heart and right kidney weights were significantly increased in 3 mg/mL females.

No changes in mice hematology parameters were attributable to Bmim-Cl exposure (Appendix E).

Estrous cycle length, number of cycles, and percentage of time spent in each respective stage of estrous were not affected by Bmim-Cl exposure. Assessment of the lengths of diestrus, proestrus, and estrus using the continuous-time Markov model did not reveal any Bmim-Cl-related differences in modeled stage lengths (Appendix E).

Limited histopathological changes were observed in male and female mice exposed to Bmim-Cl (Table 25). In the kidney, there was a positive trend in the incidences of chronic progressive nephropathy in both male and female mice. Additionally, a significant increase in the incidence of adrenal gland persistent X-zone was observed in females exposed to 3 mg/mL relative to the control group. The morphological features of the lesions discussed in this section are presented in the Histopathological Descriptions of Mice section.

Table 25 Incidences of Nonneoplastic Lesions of the Kidney and Adrenal Gland in Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride

| 0 mg/mL | 0.3 mg/mL | 1 mg/mL | 3 mg/mL
n ^a^ | 10 | 10 | 10 | 10
Male
Kidney
Nephropathy, chronic progressive^b^ | 1* (1.0)^c^ | 3 (1.0) | 0 | 5 (1.0)
Female
Kidney
Nephropathy, chronic progressive | 0* | 0 | 1 (1.0) | 3 (1.0)
Adrenal Gland
Adrenal cortex, X-zone, persistent | 0** | 1 | 0 | 5*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals; 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

#### 1-Butyl-1-Methylpyrrolidinium Chloride (Bmpy-Cl)

Male and female mice were exposed to different concentrations of Bmpy-Cl. Male mice were exposed to 0, 1, 3, or 10 mg/mL, and females were exposed to 0, 1, 3, or 6 mg/mL in drinking water. All mice survived to the end of the 3-month exposure period (Table 26), and no exposure-related clinical observations were noted (Appendix E). Only male mice exposed to 10 mg/mL had a significantly decreased terminal mean body weight compared to the control group; this finding was interpreted as lower weight gain throughout the study (Table 26; Figure 7; Appendix E). At the end of the study, the mean body weight of male mice exposed to 10 mg/mL was 84% of the control group. The terminal mean body weight of female mice exposed to 6 mg/mL was 94% of the control group.

Table 26 Summary of Survival and Mean Body Weights of Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride

Study Day^a^ | 0 mg/mL | | 1 mg/mL | | | 3 mg/mL | | | 10 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 22.6 | 10 | 22.7 | 100.4 | 10 | 22.5 | 99.8 | 10 | 22.3 | 98.6 | 10
8 | 24.1 | 10 | 24.2 | 100.4 | 10 | 24.1 | 100.1 | 10 | 21.8 | 90.6 | 10
15 | 25.5 | 10 | 25.3 | 99.1 | 10 | 25.3 | 99.3 | 10 | 23.0 | 90.0 | 10
22 | 26.4 | 10 | 26.4 | 100.0 | 10 | 26.4 | 99.8 | 10 | 23.6 | 89.3 | 10
29 | 27.4 | 10 | 26.6 | 96.8 | 10 | 27.6 | 100.5 | 10 | 24.7 | 90.1 | 10
36 | 28.8 | 10 | 28.2 | 97.8 | 10 | 28.5 | 99.1 | 10 | 25.5 | 88.6 | 10
43 | 29.5 | 10 | 29.1 | 98.8 | 10 | 29.3 | 99.4 | 10 | 26.0 | 88.0 | 10
50 | 30.8 | 10 | 30.0 | 97.6 | 10 | 30.3 | 98.6 | 10 | 26.9 | 87.4 | 10
57 | 31.9 | 10 | 31.4 | 98.4 | 10 | 31.7 | 99.3 | 10 | 27.4 | 86.0 | 10
64 | 33.0 | 10 | 33.0 | 99.9 | 10 | 33.2 | 100.6 | 10 | 28.0 | 84.9 | 10
71 | 33.6 | 10 | 33.5 | 99.7 | 10 | 33.4 | 99.4 | 10 | 28.8 | 85.6 | 10
78 | 34.7 | 10 | 34.7 | 99.9 | 10 | 34.6 | 99.6 | 10 | 29.2 | 84.2 | 10
85 | 35.7 | 10 | 36.1 | 101.2 | 10 | 35.8 | 100.3 | 10 | 29.9 | 83.7 | 10
EOS | 36.6 | 10 | 37.2 | 101.6 | 10 | 36.8 | 100.6 | 10 | 30.6 | 83.7 | 10
Study Day | 0 mg/mL | | 1 mg/mL | | | 3 mg/mL | | | 6 mg/mL
Study Day | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Female
1 | 17.2 | 10 | 17.3 | 100.9 | 10 | 17.1 | 99.5 | 10 | 17.3 | 100.9 | 10
8 | 18.0 | 10 | 18.5 | 102.8 | 10 | 17.8 | 98.9 | 10 | 18.0 | 100.1 | 10
15 | 19.5 | 10 | 19.5 | 100.1 | 10 | 18.7 | 95.8 | 10 | 18.7 | 96.2 | 10
22 | 20.6 | 10 | 20.5 | 99.6 | 10 | 19.8 | 96.1 | 10 | 19.7 | 95.7 | 10
29 | 21.8 | 10 | 21.6 | 99.2 | 10 | 20.9 | 96.1 | 10 | 20.2 | 92.6 | 10
36 | 22.8 | 10 | 22.9 | 100.6 | 10 | 21.9 | 95.9 | 10 | 22.2 | 97.5 | 10
43 | 23.2 | 10 | 23.6 | 101.9 | 10 | 22.5 | 97.2 | 10 | 22.5 | 97.2 | 10
50 | 24.2 | 10 | 24.0 | 99.3 | 10 | 21.6 | 89.1 | 10 | 23.4 | 96.8 | 10
57 | 25.5 | 10 | 24.8 | 97.6 | 10 | 23.2 | 91.2 | 10 | 24.1 | 94.7 | 10
64 | 26.0 | 10 | 25.8 | 99.3 | 10 | 25.4 | 97.7 | 10 | 24.7 | 95.0 | 10
71 | 26.8 | 10 | 26.6 | 99.4 | 10 | 25.8 | 96.2 | 10 | 25.5 | 95.3 | 10
78 | 27.6 | 10 | 26.7 | 96.7 | 10 | 27.0 | 97.8 | 10 | 26.1 | 94.7 | 10
85 | 27.7 | 10 | 26.8 | 97.0 | 10 | 26.7 | 96.7 | 10 | 25.8 | 93.2 | 10
EOS | 27.9 | 10 | 27.0 | 97.0 | 10 | 26.5 | 95.2 | 10 | 26.1 | 93.7 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 7

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride

Growth curves are shown for (A) males and (B) females.

Water consumption by male and female mice exposed to Bmpy-Cl at the highest exposure concentrations of 10 mg/mL and 6 mg/mL, respectively, was lower than that of the control groups (Table 27). Mean water consumption ranged from 61% to 81% of the control group for males and from 81% to 97% of the control group for females (Appendix E). Drinking water concentrations of 1, 3, and 10 mg/mL resulted in estimated average doses of 123, 364, and 942 mg/kg/day for males, respectively. For females, drinking water concentrations of 1, 3, and 6 mg/mL resulted in estimated average doses of 130, 403, and 696 mg/kg/day, respectively.

Table 27 Summary of Water and 1-Butyl-1-Methylpyrrolidinium Chloride Consumption of Male and Female Mice in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 1 mg/mL | 3 mg/mL | 10 mg/mL | 1 mg/mL | 3 mg/mL | 10 mg/mL
Male
2^c^ | 3.3 | 3.6 | 3.5 | 2.0 | 148.8 | 435.1 | 916.2
3 | 3.3 | 3.6 | 3.4 | 2.2 | 142.3 | 402.5 | 957.8
6 | 3.4 | 3.9 | 3.6 | 2.4 | 138.5 | 378.5 | 941.2
9 | 3.2 | 3.5 | 3.5 | 2.6 | 111.5 | 331.4 | 947.9
13 | 3.6 | 3.8 | 3.7 | 2.6 | 105.2 | 310.3 | 871.0
| 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
Female
1 | 2.9 | 2.7 | 3.9 | 2.4 | 156.0 | 685.4 | 831.9
3 | 2.5 | 2.6 | 2.2 | 2.1 | 133.3 | 353.3 | 672.4
6 | 2.9 | 2.8 | 2.5 | 2.4 | 122.1 | 342.9 | 647.8
9 | 3.1 | 3.1 | 2.9 | 2.8 | 124.8 | 374.5 | 696.8
13 | 3.2 | 3.4 | 3.2 | 3.0 | 126.8 | 359.1 | 698.5

^a^ Mean g of water consumed/animal/day.

^b^ Mg of 1-butyl-1-methylpyrrolidinium chloride consumed/kg body weight/day.

^c^ Week 1 data unavailable for male mice.

Absolute organ weights were not significantly altered in males or females exposed to Bmpy-Cl (Table 28; Appendix E); however, there were several significantly increased relative organ weights, primarily in animals exposed at the highest concentrations. Males exposed to 10 mg/mL had significantly increased relative right kidney, lung, right testis, and thymus weights compared to control animals. Because male mice exposed to 10 mg/mL also had significantly decreased terminal mean body weight, these changes were considered secondary effects of decreased body weight and/or water consumption. Males exposed to 10 mg/mL Bmpy-Cl also had significantly increased relative liver weights. This significant increase in relative liver weights was additionally observed in male mice exposed to 1 or 3 mg/mL Bmpy-Cl, despite their terminal mean body weights remaining similar to those of the control group. In females, the only significant difference observed was in relative right kidney weights, which increased in the 6 mg/mL group compared to the control group (Table 28).

Table 28 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride^a,b^

| 0 mg/mL | 1 mg/mL | 3 mg/mL | 10 mg/mL
n | 10 | 10 | 10 | 10
Male
Terminal Body Wt. (g) | 36.6 ± 0.8** | 37.2 ± 1.4 | 36.8 ± 1.1 | 30.6 ± 0.7**
Liver
Absolute (g) | 1.59 ± 0.04 | 1.71 ± 0.07 | 1.69 ± 0.06 | 1.46 ± 0.03
Relative (mg/g)^c^ | 43.51 ± 0.51** | 46.01 ± 0.59** | 45.90 ± 0.70** | 47.62 ± 0.49**
| 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
Female
Terminal Body Wt. (g) | 27.9 ± 0.9 | 27.0 ± 0.9 | 26.5 ± 0.7 | 26.1 ± 0.9
Kidney
Absolute (g) | 0.18 ± 0.00 | 0.17 ± 0.01 | 0.17 ± 0.01 | 0.18 ± 0.01
Relative (mg/g) | 6.31 ± 0.13* | 6.41 ± 0.15 | 6.55 ± 0.09 | 6.80 ± 0.15*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

At the end of the 3-month exposure period, there were positive trends and significant but minimal (<3%) increases in the male mice hematocrit and erythrocyte count in the 3 mg/mL and/or 10 mg/mL groups compared to the control group (Appendix E). While these changes may represent mild hemoconcentration due to lower water consumption, they were small in magnitude and might have resulted from biological variability.

Estrous cycle length and number of cycles were not affected by Bmpy-Cl exposure (Appendix E). The 1 mg/mL group displayed a greater percentage of time spent in estrus, and the continuous-time Markov model comparison of estrus stage length attained significance and was increased by 0.6 days. Inspection of the daily cyclicity observations revealed five control mice that displayed apparently longer cycles, resulting in fewer observations of estrus and metestrus. Although this response is common in control mice, five is a higher frequency than typically observed in a group size of 10; a frequency of two or three is more common, as observed in the 3 and 6 mg/mL groups. In contrast, all mice in the 1 mg/mL group displayed prototypical cycling. Given this finding, the apparent response in the 1 mg/mL group is considered spurious and not the result of Bmpy-Cl exposure.

Limited histopathological changes were observed in male and female mice exposed to Bmpy-Cl (Table 29). In the kidney, a significant increase in the incidence of renal tubule cytoplasmic alteration was found in males exposed to 10 mg/mL compared to the control group. In the adrenal gland of female mice, significant increases in the incidences of adrenal cortex persistent X-zone were found in the 3 and 6 mg/mL groups compared to the control group. The morphological features of the lesions discussed in this section are presented in the Histopathological Descriptions of Mice section.

Table 29 Incidences of Nonneoplastic Lesions of the Kidney and Adrenal Gland in Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride

| 0 mg/mL | 1 mg/mL | 3 mg/mL | 10 mg/mL
n ^a^ | 10 | 10 | 10 | 10
Male
Kidney
Renal tubule, cytoplasmic alteration^b^ | 0** | 0 | 0 | 5* (1.8)^c^
| 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
Female
Adrenal Gland
Adrenal cortex, X-zone, persistent | 0* | 1 | 4* | 4*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals; 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

#### N-Butylpyridinium Chloride (NBuPy-Cl)

Male and female mice were exposed to NBuPy-Cl at concentrations of 0, 1, 3, or 6 mg/mL in drinking water. All mice survived to the end of the 3-month exposure period (Table 30), and no exposure-related clinical observations were noted (Appendix E). Decreases in terminal mean body weights, interpreted as lower weight gain over the course of the study, were noted for male and female mice (Table 30; Figure 8; Appendix E). Terminal mean body weights were 98%, 94%, and 72% of control males for the 1, 3, and 6 mg/mL groups, respectively. Females in the same exposed groups had terminal mean body weights that were 95%, 91%, and 83%, respectively, of the control group. These changes were significant in the 3 mg/mL NBuPy-Cl-exposed females and the 6 mg/mL NBuPy-Cl-exposed males and females.

Table 30 Summary of Survival and Mean Body Weights of Male and Female Mice in the Three-month Drinking Water Study of N-Butylpyridinium Chloride

Study Day^a^ | 0 mg/mL | | 1 mg/mL | | | 3 mg/mL | | | 6 mg/mL
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
Male
1 | 23.3 | 10 | 23.7 | 101.7 | 10 | 23.6 | 101.1 | 10 | 23.5 | 100.9 | 10
8 | 25.1 | 10 | 25.0 | 99.9 | 10 | 24.9 | 99.3 | 10 | 21.7 | 86.4 | 10
15 | 25.9 | 10 | 26.1 | 100.9 | 10 | 26.2 | 101.0 | 10 | 22.9 | 88.3 | 10
22 | 27.0 | 10 | 27.1 | 100.4 | 10 | 26.5 | 98.3 | 10 | 23.4 | 86.6 | 10
29 | 28.3 | 10 | 28.5 | 100.6 | 10 | 27.8 | 98.2 | 10 | 24.3 | 85.7 | 10
36 | 29.2 | 10 | 29.5 | 101.3 | 10 | 28.6 | 98.2 | 10 | 23.2 | 79.6 | 10
43 | 30.7 | 10 | 30.8 | 100.4 | 10 | 29.7 | 96.9 | 10 | 23.3 | 76.0 | 10
50 | 31.6 | 10 | 31.8 | 100.9 | 10 | 31.0 | 98.2 | 10 | 25.2 | 79.7 | 10
57 | 33.0 | 10 | 32.9 | 99.5 | 10 | 32.0 | 97.0 | 10 | 25.4 | 77.0 | 10
64 | 33.8 | 10 | 33.8 | 99.9 | 10 | 32.6 | 96.5 | 10 | 25.7 | 76.1 | 10
71 | 35.2 | 10 | 34.9 | 99.1 | 10 | 33.8 | 95.8 | 10 | 26.6 | 75.5 | 10
78 | 35.6 | 10 | 35.3 | 99.2 | 10 | 34.0 | 95.6 | 10 | 26.9 | 75.4 | 10
85 | 36.7 | 10 | 36.1 | 98.4 | 10 | 34.7 | 94.6 | 10 | 26.6 | 72.6 | 10
EOS | 38.0 | 10 | 37.1 | 97.6 | 10 | 35.6 | 93.7 | 10 | 27.3 | 71.7 | 10
Female
1 | 17.7 | 10 | 17.5 | 98.8 | 10 | 17.5 | 98.6 | 10 | 17.2 | 97.0 | 10
8 | 18.7 | 10 | 18.4 | 98.2 | 10 | 18.3 | 97.6 | 10 | 16.5 | 88.0 | 10
15 | 20.1 | 10 | 19.7 | 98.0 | 10 | 19.4 | 96.6 | 10 | 17.6 | 87.4 | 10
22 | 20.7 | 10 | 20.4 | 98.6 | 10 | 20.2 | 97.5 | 10 | 18.8 | 90.8 | 10
29 | 22.0 | 10 | 21.8 | 99.4 | 10 | 21.2 | 96.5 | 10 | 19.5 | 88.8 | 10
36 | 23.0 | 10 | 22.4 | 97.3 | 10 | 22.1 | 96.3 | 10 | 20.2 | 88.1 | 10
43 | 24.4 | 10 | 23.4 | 96.2 | 10 | 22.9 | 94.1 | 10 | 20.9 | 85.8 | 10
50 | 24.5 | 10 | 24.0 | 98.0 | 10 | 23.2 | 94.4 | 10 | 21.6 | 88.1 | 10
57 | 25.4 | 10 | 24.7 | 97.0 | 10 | 24.2 | 95.0 | 10 | 22.2 | 87.2 | 10
64 | 26.1 | 10 | 25.0 | 95.9 | 10 | 24.1 | 92.5 | 10 | 22.3 | 85.5 | 10
71 | 27.3 | 10 | 26.2 | 96.0 | 10 | 25.1 | 91.9 | 10 | 22.9 | 83.8 | 10
78 | 27.8 | 10 | 25.9 | 93.1 | 10 | 24.7 | 88.6 | 10 | 22.4 | 80.4 | 10
85 | 27.7 | 10 | 26.4 | 95.3 | 10 | 24.9 | 89.7 | 10 | 22.5 | 81.2 | 10
EOS | 27.5 | 10 | 26.2 | 95.4 | 10 | 25.1 | 91.4 | 10 | 22.8 | 82.9 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 8

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of N-Butylpyridinium Chloride

Growth curves are shown for (A) males and (B) females.

In general, water consumption decreased in an exposure concentration-dependent manner for both male and female mice exposed to NBuPy-Cl (Table 31; Appendix E). In the highest exposed groups (6 mg/mL), water consumption by male mice ranged from 49% to 65% of control males, and water consumption by female mice ranged from 46% to 63% of control females. Drinking water concentrations of 1, 3, and 6 mg/mL resulted in estimated average doses of 118, 310, and 483 mg/kg/day, respectively, for males and 125, 331, and 518 mg/kg/day, respectively, for females.

Table 31 Summary of Water and N-Butylpyridinium Chloride Consumption of Male and Female Mice in the Three-month Drinking Water Study

Week | Water (g/day)^a^ | | | | Dose (mg/kg/day)^b^
Week | 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
Male
2^c^ | 3.7 | 3.7 | 3.4 | 1.8 | 147.8 | 410.0 | 498.8
3 | 3.4 | 3.5 | 2.9 | 2.0 | 133.9 | 332.6 | 524.7
6 | 3.2 | 3.4 | 3.0 | 2.0 | 115.1 | 314.2 | 516.8
9 | 3.6 | 3.7 | 2.9 | 1.9 | 112.6 | 271.5 | 448.5
13 | 3.5 | 3.4 | 3.0 | 1.9 | 94.1 | 259.2 | 427.9
Female
1 | 2.8 | 2.7 | 2.4 | 1.3 | 154.6 | 412.6 | 454.5
3 | 2.6 | 2.6 | 2.0 | 1.5 | 132.0 | 309.1 | 512.5
6 | 3.1 | 2.7 | 2.4 | 1.8 | 120.8 | 325.2 | 533.6
9 | 3.3 | 3.0 | 2.7 | 1.9 | 121.6 | 335.3 | 514.0
13 | 3.4 | 3.3 | 2.7 | 2.0 | 124.9 | 325.8 | 533.1

^a^ Mean g of water consumed/animal/day.

^b^ Mg of n-butylpyridinium chloride consumed/kg body weight/day.

^c^ Week 1 data unavailable for male mice.

Various significant organ weight changes were observed for both male and female mice exposed to NBuPy-Cl (Table 32; Appendix E). Male mice exposed to 6 mg/mL had a significantly decreased terminal mean body weight compared to the control group, accompanied by significantly decreased absolute right kidney, liver, lung, and thymus weights and significantly increased relative right kidney, liver, and right testis weights. Female mice exposed to 6 mg/mL had a significantly decreased terminal mean body weight compared to the control group, accompanied by significantly decreased absolute lung weights and significantly increased relative heart, right kidney, and liver weights. Female mice exposed to 3 mg/mL also had a significantly decreased terminal mean body weight and significantly increased relative heart and right kidney weights. All these organ weight changes were considered secondary effects of decreased body weight and/or water consumption (Appendix E). In contrast, male mice exposed to 3 mg/mL did not have a significantly decreased terminal mean body weight but did have significantly increased relative right kidney and liver weights compared to the control group (Table 32).

Table 32 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Mice in the Three-month Drinking Water Study of N-Butylpyridinium Chloride^a,b^

| 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
n | 10 | 10 | 10 | 10
Terminal Body Wt. (g) | 38.0 ± 1.3** | 37.1 ± 1.1 | 35.6 ± 1.5 | 27.3 ± 0.6**
Right Kidney
Absolute (g) | 0.31 ± 0.01* | 0.32 ± 0.01 | 0.32 ± 0.01 | 0.27 ± 0.01*
Relative (mg/g)^c^ | 8.16 ± 0.21** | 8.57 ± 0.16 | 8.91 ± 0.20** | 9.89 ± 0.15**
Liver
Absolute (g) | 1.73 ± 0.06** | 1.66 ± 0.05 | 1.70 ± 0.08 | 1.40 ± 0.03**
Relative (mg/g) | 45.65 ± 0.67** | 44.88 ± 0.44 | 47.74 ± 0.64* | 51.22 ± 0.73**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

At the end of the 3-month exposure period, neutrophil counts in male mice exposed to 3 or 6 mg/mL were significantly decreased relative to the control group (Appendix E). Given that these changes were small in magnitude and not observed in the rats or female mice, the toxicological significance of the decreased neutrophil counts in the male mice is unknown. No hematological effects were observed in female mice.

Estrous cycle length, number of cycles, and percentage of time spent in each respective stage of estrous were not affected by NBuPy-Cl exposure. Assessment of the lengths of diestrus, proestrus, and estrus using the continuous-time Markov model did not reveal any NBuPy-Cl-related differences in modeled stage lengths (Appendix E).

Limited histopathological changes were observed in male and female mice exposed to NBuPy-Cl (Table 33). Significant increases in the incidences of chronic progressive nephropathy and renal tubule cytoplasmic alteration were observed in the kidneys of male mice exposed to 6 mg/mL compared to the control group. There was also a positive trend in the incidence of chronic progressive nephropathy in female mice. In the adrenal gland of female mice, there was a significant increase in the incidence of adrenal cortex persistent X-zone at 6 mg/mL compared to the control group. The morphological features of the lesions discussed in this section are presented in the Histopathological Descriptions of Mice section.

Table 33 Incidences of Nonneoplastic Lesions of the Kidney and Adrenal Gland in Male and Female Mice in the Three-month Drinking Water Study of N-Butylpyridinium Chloride

| 0 mg/mL | 1 mg/mL | 3 mg/mL | 6 mg/mL
n ^a^ | 10 | 10 | 10 | 10
Male
Kidney
Nephropathy, chronic progressive^b^ | 2** (1.0)^c^ | 0 | 4 (1.0) | 8* (1.0)
Renal tubule, cytoplasmic alteration | 0** | 0 | 0 | 10** (2.0)
Female
Kidney
Nephropathy, chronic progressive | 2* (1.0) | 0 | 2 (1.0) | 5 (1.0)
Adrenal Gland
Adrenal cortex, X-zone, persistent | 0** | 2 | 3 | 9**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals; 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

#### Histopathological Descriptions of Mice

In general, the histopathological changes, when present in the kidney and adrenal gland, were morphologically similar across studies.

Kidney: Chronic progressive nephropathy (CPN) was generally characterized by minimal focal to multifocal cytoplasmic basophilia and nuclear crowding of the proximal and distal tubular epithelium (Figure 9). The tubular basophilia is evidence of cellular regeneration. CPN has been more extensively studied in rats than in mice; its incidence and/or severity is influenced by a variety of factors, such as hormones, caloric intake, protein content of diet, and some xenobiotics.^104^

Figure 9

Representative Image of Chronic Progressive Nephropathy in the Kidney of a Male Mouse in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride (H&E)

Chronic progressive nephropathy was characterized by focal to multifocal cytoplasmic basophilia and nuclear crowding of the proximal and distal tubular epithelium (arrows) as illustrated in this image from the kidney of a male mouse exposed to 3 mg/mL 1-butyl-3-methylimidazolium chloride (14.8x). H&E = hematoxylin and eosin stain.

Renal tubule cytoplasmic alteration was generally characterized by a reduction in the renal tubule cytoplasmic vacuolization normally seen in the outer cortical tubules of male mice (Figure 10). The presence of cytoplasmic vacuoles is a sexually dimorphic lesion, occurring only in males, and is thought to represent autophagic vacuoles associated with the normal degeneration of renal tubular epithelial cells.^105^

Figure 10

Representative Images of Renal Tubule Cytoplasmic Alteration in the Kidney of Male Mice in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride (H&E)

Cytoplasmic alteration of the renal tubules is a lesion specific to the kidneys of male mice, characterized by a reduction in the renal tubule cytoplasmic vacuolization that is normally seen in the outer cortical tubules. Compare normal vacuoles in cortical renal tubules in a control male mouse (panel A at 4x and panel B at 20x) to the markedly fewer vacuoles from a male mouse exposed to 10 mg/mL 1-butyl-1-methylpyrrolidinium chloride (panel C at 4x and panel D at 20x). H&E = hematoxylin and eosin stain.

Adrenal gland: Adrenal cortex persistent X-zone was characterized by reduced numbers or the absence of X-zone cells undergoing vacuolar degeneration (Figure 11). The X-zone is a transient region in young mice at the cortical-medullary boundary of the adrenal gland, appearing a few days after birth in both sexes. The cells in the X-zone are darker and smaller, and the cytoplasm is more basophilic than those in the zona fasciculata. The function of the X-zone is not known, but during development, these fetal cortical cells are gradually replaced by newly formed adult cortical cells that develop into outer definitive zones. In the male mouse, this zone disappears rapidly with the approach of puberty (approximately 5 weeks of age) due to androgen signaling via the androgen receptor.^106^ In female virgins, the X-zone continues to grow in size until about 9 weeks of age and then regresses gradually.

Figure 11

Representative Images of Persistent X-zone in the Adrenal Gland of Female Mice in the Three-month Drinking Water Study of N-Butylpyridinium Chloride (H&E)

Persistent X-zone was characterized by reduced numbers or the absence of cells at the cortico-medullary boundary of the adrenal gland undergoing vacuolar degeneration. Compare the normal degenerating vacuolated cells at the cortico-medullary junction in a control female mouse (panel A at 4x and panel B at 36.4x) to the markedly fewer vacuolated cells from a female mouse exposed to 6 mg/mL n-butylpyridinium chloride (panel C at 4x and panel D at 36.4x). H&E = hematoxylin and eosin stain, M = medulla, X = X-zone, C = cortex.

### Genetic Toxicology

All four ILs were tested for induction of gene mutations in three strains of bacteria (Salmonella typhimurium strains TA98 and TA100, and Escherichia coli strain WP2 uvrA [pKM101]), as well as induction of structural or numerical chromosomal damage in the rodent peripheral blood erythrocyte micronucleus (MN) assay using samples collected from the 3-month study in rats and mice. Data from all NTP genetic toxicity tests with Emim-Cl, Bmim-Cl, Bmpy-Cl, and NBuPy-Cl are presented in Appendix D.

None of the four ILs induced mutations in the three strains of bacteria in studies conducted with and without induced rat liver S9 mix at doses up to 10,000 μg/plate.

Results of the MN assay were somewhat variable across the four ILs. Emim-Cl did not increase the frequency of micronucleated erythrocytes in male or female rats or in male mice. In female mice, the MN assay response was also judged to be negative, although a small, significant increase was observed in micronucleated mature erythrocytes; this response was not considered of sufficient magnitude to be biologically relevant and was well within the laboratory historical control 95% confidence interval for female B6C3F1 mice.

No increases in micronucleated erythrocytes were seen in blood samples from Bmim-Cl-exposed rats and mice.

For Bmpy-Cl-exposed animals, a clearly positive response was seen in the immature erythrocyte population in male rat peripheral blood samples (the appropriate cell population used to assess MN in rats). Results were negative for female rats as well as male and female mice.

The response in NBuPy-Cl-exposed male rats was judged to be equivocal. Although there was a significant increase in micronucleated mature erythrocytes, the results for immature erythrocytes were negative. Because this response pattern is in direct contrast to what would be expected in rats for a truly positive compound, the increases observed were within the laboratory 95% confidence interval for male rats, and there is no biological explanation for the observation (such as altered spleen function) in these rats, the response was judged to be equivocal. No differences in MN frequencies were observed in female rats or male and female mice for either cell population.