# Materials and Methods

## Procurement and Characterization of Ionic Liquids

1‐Ethyl‐3‐methylimidazolium chloride (Emim-Cl) was obtained from Sigma-Aldrich (St. Louis, MO) in three lots (S37784, S46787, and STBB3624); 1-butyl-3-methylimidazolium chloride (Bmim-Cl) was obtained from Solvent Innovations (Koln, Germany) in a single lot (99/787) and from Sigma-Aldrich (St. Louis, MO) in a single lot (STBB3444); 1-butyl-1-methylpyrrolidinium chloride (Bmpy-Cl) was obtained from Solvent Innovations (Koln, Germany) in a single lot (99/831) and from Promy Chemical, Inc. (El Sobrante, CA) in a single lot (20100610); and n-butylpyridinium chloride (NBuPy-Cl) was obtained from Solvent Innovations (Koln, Germany) in a single lot (99/830) and from Promy Chemical, Inc. (El Sobrante, CA) in a single lot (20100610). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) (Appendix A). Reports on analyses performed in support of the ionic liquid (IL) studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot S37784 (Emim-Cl), a faint yellow solid; lot S46787 (Emim-Cl), a brown solid; lot STBB3624 (Emim-Cl), a yellow-brown solid; lot 99/787 (Bmim-Cl), a pale amber solid; lot STBB3444 (Bmim-Cl), a solid white mass with small orange streaks; lot 99/831 (Bmpy-Cl), a white chunky powder; lot 20100610 (Bmpy-Cl), a pale-yellow crystalline powder; lot 99/830 (NBuPy-Cl), an off-white solid with a peach hue; and lot 20100610 (NBuPy-Cl), a pale-yellow crystalline powder, were identified using infrared (IR) spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, and mass spectrometry (MS). In addition, elemental analysis was performed by Prevalere Life Sciences, Inc. (Whitesboro, NY) to confirm the identity of each compound.

The purity of each IL was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV), evaporative light scattering detection (ELSD), or charged aerosol detection (CAD) (Table A-1). Residual solvent content was determined by weight loss on drying or headspace gas chromatography (GC/headspace) with flame ionization detection (FID), and any impurities were identified using GC with MS detection. The chloride content of each IL was quantified using ion chromatography (IC). Moisture content was measured for each IL using Karl Fischer titration; however, the calculated results are estimates due to the hygroscopic nature of these compounds. The analytical methods and systems used for each respective lot are described in detail in Appendix A. Purity analysis results for each lot are listed in Table 2.

Table 2 Purity of Chemicals in the Two-week and Three-month Drinking Water Studies of Ionic Liquids

Chemical | Lot Number | Water (%)^a^ | Elemental Analysis (%)^b^ | | | | Cl (% w/w)^c^ | Overall Purity (%) | Impurities (%)^d^
Chemical | Lot Number | Water (%)^a^ | C | H | N | Cl | Cl (% w/w)^c^ | Overall Purity (%) | Impurities (%)^d^
Emim-Cl | S37784 | 0.2 | 49.01 | 7.46 | 18.60 | 24.17 | 23.80 ± 0.14 | >99 | <0.05
| S46787 | 0.6 | 49.17 | 7.82 | 18.81 | 24.37 | 23.50 ± 0.08 | >99 | <0.05
| STBB3624 | 1.1 | 47.27 | 7.86 | 17.66 | 22.19 | 22.26 ± 0.33 | >99 | <0.05
Bmim-Cl | 99/787 | 0.5 | 54.64 | 8.91 | 15.83 | 19.91 | 20.01 ± 0.02 | >99 | <0.05
| STBB3444 | 0.7 | 53.72 | 8.71 | 14.98 | 18.92 | 19.28 ± 0.43 | >99 | <0.05
Bmpy-Cl | 99/831 | 0.5 | 60.29 | 11.66 | 7.78 | 19.97 | 19.71 ± 0.27 | >99 | <0.05
| 20100610 | 1.2 | 60.43 | 11.26 | 7.50 | 20.67 | 19.16 ± 0.65 | >98 | <0.05
NBuPy-Cl | 99/830 | 0.3 | 62.75 | 8.31 | 7.99 | 20.57 | 20.47 ± 0.13 | >99 | 0.61^e^
| 20100610 | 0.5 | 62.66 | 8.21 | 7.72 | 20.49 | 20.25 ± 0.11 | >98 | 0.73^e^

Emim-Cl = 1-ethyl-3-methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

^a^ Estimates determined by Karl Fischer titration.

^b^ Theoretical values (%): Emim-Cl: C, 49.2; H, 7.6; N, 19.1; Cl, 24.2; Bmim-Cl: C, 55.0; H 8.7; N 16.0; Cl 20.3; Bmpy-Cl: C, 60.8; H, 11.3; N 7.9; Cl, 19.9; NBuPy-Cl: C, 63.0; H 8.2; N 8.2; Cl 20.7

^c^ Determined by ion chromatography; mean ± standard deviation.

^d^ Determined by high-performance liquid chromatography with evaporative light scattering detection (HPLC/ELSD); limit of detection ≥0.05%.

^e^ Determined by high-performance liquid chromatography with ultraviolet detection (HPLC/UV).

Accelerated stability studies were conducted on samples of lots STBB3624 (Emim-Cl), STBB3444 (Bmim-Cl), 20100610 (Bmpy-Cl), and 20100610 (NBuPy-Cl). Samples were stored for 2 weeks under an inert headspace in amber glass vials sealed with Teflon^®^-lined screw-top lids at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures. Stability was confirmed for all analyzed lots at all four temperatures. The bulk chemicals (all lots) were stored at room temperature in sealed amber glass containers under inert gas headspace. Reanalysis of the bulk chemicals on all lots except S46787 (Emim-Cl) were performed, and no degradation was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations for the 2-week study were prepared once at MRIGlobal (Kansas City, MO) by mixing Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl with tap water to give the required concentrations (Table 3). Dose formulations of Emim-Cl were prepared with lot S37784, except for the 100 mg/mL formulation, which was a combination of lots S37784 and S46787. Dose formulations of Bmim-Cl, Bmpy-Cl, and NBuPy-Cl were prepared with lots 99/787, 99/831, and 99/830, respectively (Table A-3).

Table 3 Experimental Design and Materials and Methods in the Two-week Drinking Water Studies of Ionic Liquids

Rats | Mice
Study Laboratory
BioReliance (Rockville, MD) | Same as in rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
Males: 11 days | Males: 14 days
Females: 12 days | Females: 15 days
Average Age When Studies Began
6 weeks | Same as in rats
Date of First Exposure
March 9 (males) or 10 (females), 2009 | March 12 (males) or 13 (females), 2009
Duration of Exposure
2 weeks | Same as in rats
Date of Last Exposure
March 23 (males) or 24 (females), 2009 | March 26 (males) or 27 (females), 2009
Necropsy Dates
March 23 (males) or 24 (females), 2009 | March 26 (males) or 27 (females), 2009
Average Age at Necropsy
8 weeks | Same as in rats
Size of Study Groups
10 males and 10 females for control groups 5 males and 5 females for exposed groups | Same as in rats
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as in rats
Animals per Cage
5 | 1 (male) or 5 (female)
Method of Animal Identification
Tail tattoo | Same as in rats
Diet
Irradiated NTP-2000 pelleted feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as in rats
Water
Tap water (Potomac, MD municipal supply), either untreated or containing a formulation of Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl via amber glass bottles, available ad libitum, changed twice weekly | Same as in rats
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed at least twice weekly | Same as in rats
Cage Filters
Omnishield paper, Reemay^®^ 2024 (DuPont), changed every 2 weeks | Same as in rats
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as in rats
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks | Same as in rats
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as in rats
Exposure Concentrations
Emim-Cl: 0, 3, 10, 30, or 100 mg/mL | Emim-Cl: Same as in rats
Bmim-Cl: 0, 0.3, 1, or 3 mg/mL | Bmim-Cl: 0, 1, 3, or 6 mg/mL
Bmpy-Cl: 0, 1, 3, or 6 mg/mL | Bmpy-Cl: 0, 3, 6, or 10 mg/mL
NBuPy-Cl: 0, 1, 3, or 6 mg/mL | NBuPy-Cl: Same as in rats
Type and Frequency of Observation
Observed twice daily; animals were weighed, and clinical observations were recorded initially, on study day 8, and at the end of the 2-week exposure period. Water consumption was recorded on study days 1, 4, 8, 11, 14, and 15. | Observed twice daily; animals were weighed, and clinical observations were recorded initially, on study day 8, and at the end of the 2-week exposure period. Water consumption was recorded on study days 1, 5, 8, 12, and 15.
Method of Euthanasia
100% carbon dioxide | Same as in rats
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lungs, right testis, and thymus. | Same as in rats
Histopathology
Complete histopathology was performed on all control animals and all animals in the highest exposed groups. In addition to gross lesions and tissue masses, the following tissues were examined: brain, heart, kidney, liver, lung, ovary, stomach (forestomach and glandular), small intestine, spleen, testes, and thymus. | Same as in rats

Emim-Cl = 1‐ethyl‐3‐methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

Homogeneity was confirmed for the highest and lowest dose formulations of each IL. Stability studies were completed for representative formulations of each IL and are described in Appendix A. The storage stability of Emim-Cl, Bmim-C, Bmpy-Cl, and NBuPy-Cl was confirmed at refrigerated temperatures when protected from light for up to 21 days, 42 days, 42 days, and 35 days, respectively. All dose formulations were stored protected from light at refrigerated temperatures (2°C–8°C) for ≤7 days until shipment to the study laboratory (BioReliance, Rockville, MD). At the study laboratory, all dose formulations were stored protected from light in a plastic carboy at refrigerated temperatures (2°C–8°C) and used within 42 days.

Analyses of preadministration and postadministration dose formulations for the 2-week studies of Emim-Cl, Bmim-Cl, and NBuPy-Cl were conducted once for each study by the MRIGlobal analytical chemistry laboratory using HPLC/UV. HPLC/ELSD was used to conduct analysis of preadministration and postadministration dose formulations of Bmpy-Cl. Postadministration dose formulation analysis results are averages from animal room drinking water bottles and bulk containers. All dose formulations were within 10% of the target concentrations for all four chemicals (Emim-Cl [Table A-5], Bmim-Cl [Table A-8], Bmpy-Cl [Table A-11], and NBuPy-Cl [Table A-14]). The pH of the Emim-Cl and Bmpy-Cl dose formulations was measured postadministration and is reported in Table A-17 and Table A-18, respectively. pH ranged from 7.1 to 9.1 across all samples.

The dose formulations for the 3-month studies were prepared at the Battelle study laboratory (Columbus, OH) by mixing Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl with tap water to give the required concentrations for each species (Table 4). Dose formulations were prepared with lots STBB3624 (Emim-Cl), STBB3444 (Bmim-Cl), 20100610 (Bmpy-Cl), and 20100610 (NBuPy-Cl), respectively (Table A-4). Stability and homogeneity studies were completed for representative formulations of each IL and described in Appendix A. All four IL dose formulations were considered stable for ≤42 days when stored refrigerated or at room temperature, protected from light. The formulations were stored protected from light in a plastic carboy at refrigerated temperatures (2°C–8°C). Emim-Cl and NBuPy-Cl formulations were used within 35 days of preparation, and Bmim-Cl and Bmpy-Cl formulations were used within 42 days of preparation.

Table 4 Experimental Design and Materials and Methods in the Three-month Drinking Water Studies of Ionic Liquids

Rats | Mice
Study Laboratory
Battelle (Columbus, OH) | Same as in rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
12 days | Same as in rats
Average Age When Studies Began
5–7 weeks | Same as in rats
Date of First Exposure
Emim-Cl: May 9 (males) or 10 (females), 2013 | Emim-Cl: May 8 (males) or 7 (females), 2013
Bmim-Cl: April 25 (males) or 26 (females), 2013 | Bmim-Cl: April 24 (males) or 23 (females), 2013
Bmpy-Cl: August 22 (males) or 23 (females), 2013 | Bmpy-Cl: August 21 (males) or 20 (females), 2013
NBuPy-Cl: September 19 (males) or 20 (females), 2013 | NBuPy-Cl: September 18 (males) or 17 (females), 2013
Duration of Exposure
3 months | Same as in rats
Date of Last Exposure
Emim-Cl: August 8 (males) or 9 (females), 2013 | Emim-Cl: August 7 (males) or 6 (females), 2013
Bmim-Cl: July 25 (males), or 26 (females), 2013 | Bmim-Cl: July 24 (males) or 23 (females), 2013
Bmpy-Cl: November 21 (males) or 22 (females), 2013 | Bmpy-Cl: November 20 (males) or 19 (females), 2013
NBuPy-Cl: December 19 (males) or 20 (females), 2013 | NBuPy-Cl: December 18 (males) or 17 (females), 2013
Necropsy Dates
Emim-Cl: August 8 (males) or 9 (females), 2013 | Emim-Cl: August 7 (males) or 6 (females), 2013
Bmim-Cl: July 25 (males) or 26 (females), 2013 | Bmim-Cl: July 24 (males) or 23 (females), 2013
Bmpy-Cl: November 21 (males) or 22 (females), 2013 | Bmpy-Cl: November 20 (males) or 19 (females), 2013
NBuPy-Cl: December 19 (males) or 20 (females), 2013 | NBuPy-Cl: December 18 (males) or 17 (females), 2013
Average Age at Necropsy
18–20 weeks | Same as in rats
Size of Study Groups
10 males and 10 females | Same as in rats
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as in rats
Animals per Cage
Up to 3 (male), up to 5 (female) | 1 (male), up to 4 (female)
Method of Animal Identification
Tail tattoo | Same as in rats
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Gardners, PA), available ad libitum, changed weekly | Same as in rats
Water
Tap water (Columbus, OH municipal supply), either untreated or containing a formulation of Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl via glass bottles (Thermo Fisher Scientific, Waltham, MA), available ad libitum, changed twice weekly | Tap water (Columbus, OH municipal supply), either untreated or containing a formulation of Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl via glass bottles (Sigma-Aldrich Corp., St. Louis, MO [male mice] or Qorpak, Clinton, PA [female mice]), available ad libitum, changed once (males) or twice (females) weekly.
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed at least twice weekly | Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed at least once (males) or twice (females) weekly
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as in rats
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated at least every 2 weeks | Same as in rats
Rack Filters
Spun-bonded polyester (National Filter Media Corporation, Salt Lake City, UT), changed at least every 2 weeks | Same as in rats
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 43%−74% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72°F ± 3°F Relative humidity: 43%−67% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
Emim-Cl: 0, 1, 3, or 10 mg/mL | Emim-Cl: 0, 3, 10, or 30 mg/mL
Bmim-Cl: 0, 0.1, 0.3, or 1 mg/mL | Bmim-Cl: 0, 0.3, 1, or 3 mg/mL
Bmpy-Cl: 0, 0.3 (males only), 1, 3, or 6 (females only) mg/mL | Bmpy-Cl: 0, 1, 3, 6 (females only), or 10 (males only) mg/mL
NBuPy-Cl: 0, 0.3, 1, or 3 mg/mL | NBuPy-Cl: 0, 1, 3, or 6 mg/mL
Type and Frequency of Observation
Observed twice daily; animals were weighed, and clinical observations were recorded initially, weekly thereafter, and at the end of the 3-month exposure period. Water consumption was recorded at least weekly for the duration of the study. | Same as in rats
Method of Euthanasia
100% carbon dioxide | Same as in rats
Necropsy
Necropsies were performed on all animals. Organs weighed were the heart, right kidney, liver, lungs, right testis, and thymus. | Same as in rats
Clinical Pathology
At the end of the 3-month exposure period, blood was collected from the retroorbital plexus of rats for clinical chemistry, hematology, and erythrocyte micronuclei determination. | At the end of the 3-month exposure period, blood was collected from the retroorbital sinus of mice for hematology and erythrocyte micronuclei determination.
Hematology: erythrocyte count, mean corpuscular volume, hemoglobin, hematocrit, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, white blood cell count and differential, reticulocyte count, platelet count, and qualitative evaluation of morphological features in all cellular components. | Same as in rats
Clinical chemistry: alkaline phosphatase, alanine aminotransferase, sorbitol dehydrogenase, total protein, albumin, globulin, A/G ratio, glucose, urea nitrogen, creatinine, creatine kinase, triglyceride, cholesterol, and total bile acids. | None
Histopathology
Complete histopathology was performed on all control animals and all animals in the highest exposed groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (olfactory bulbs, fronto-parietal cortex and basal ganglia, mid-parietal cortex and thalamus, mid-brain with substantia nigra and red nucleus, posterior colliculi, mid-cerebellum including cranial nerve VIII, and posterior medulla), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), Harderian glands, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates (three sections), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, spleen, stomach (forestomach and glandular), right testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all control animals and all animals in the highest exposed groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (olfactory bulbs, fronto-parietal cortex and basal ganglia, mid-parietal cortex and thalamus, mid-brain with substantia nigra and red nucleus, posterior colliculi, mid-cerebellum including cranial nerve VIII, and posterior medulla), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), gallbladder, Harderian glands, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates (three sections), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, spleen, stomach (forestomach and glandular), right testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. Because exposure-related observations were noted in the kidneys of male and female mice and in the adrenal glands of female mice at the highest concentrations for Emim-Cl, Bmim-Cl, Bmpy-Cl, and NBuPy-Cl, the kidneys were examined for male and female mice and the adrenal glands were examined for all female mice in all exposure groups for all four ILs.
Sperm Motility and Vaginal Cytology
At the end of the 3-month exposure period, sperm samples were collected from all male rats for sperm motility evaluations. Sperm motility and sperm/spermatid concentration data were not analyzed or reported due to artifacts identified during analysis. The right testis was weighed. Vaginal samples were collected for up to 16 consecutive days before the end of the 3-month exposure period from all female rats for vaginal cytology evaluations. | Same as in rats

Emim-Cl = 1‐eethyl‐3‐methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

Analyses of preadministration and postadministration dose formulations for the 3-month studies of Emim-Cl, Bmim-Cl, and NBuPy-Cl were conducted once after each new formulation was prepared at the Battelle study laboratory using HPLC/UV. HPLC/CAD was used to conduct similar analyses of the dose formulations for the 3-month study of Bmpy-Cl. All preadministration dose formulations for all four chemicals were within 10% of the target concentrations. All animal room samples for Emim-Cl (Table A-6, Table A-7) and Bmim-Cl (Table A-9, Table A-10) were within 10% of the target concentrations. All animal room samples for Bmpy-Cl (Table A-12, Table A-13) were within 10% of the target concentrations, apart from three samples for the rat study and five samples for the mouse study (10.7%–15.8%). All animal room samples for NBuPy-Cl (Table A-15, Table A-16) were within 10% of the target concentrations, apart from one carboy sample for the rat study, which was 13.1% above the target concentration.

## Animal Source

Male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN). Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the BioReliance (Rockville, MD) and Battelle (Columbus, OH) Animal Care and Use Committees and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Studies

The 2-week dose range-finding studies were designed to run concurrently. Thus, all four ILs evaluated for toxicity were compared to the same set of control animals. Details of the experimental design are shown in Table 3. Concentrations for the 2-week studies were informed by the water solubility of each IL and preliminary palatability studies (e.g., changes in mortality, clinical signs of toxicity, body weight decreases, and feed/water consumption) in rats and mice (data not shown). Additional information in the literature suggested that Emim-Cl was less toxic than Bmim-Cl. Therefore, a high exposure concentration of 100 mg/mL was selected for Emim-Cl on the basis of a 10% drinking water concentration, and three lower concentrations were selected to provide overlapping concentrations with the other compounds. Data from the 2-week studies were evaluated for selection of concentrations to be used in the 3-month exposure studies.

Rats and mice were approximately 4 weeks old on receipt. Animals were quarantined for 11 days (male rats), 12 days (female rats), 14 days (male mice), or 15 days (female mice) and were approximately 6 weeks old on the first day of the studies. Rats and mice were randomly assigned to either the control group or one of three (Bmim-Cl, Bmpy-Cl, and NBuPy-Cl) or four (Emim-Cl) exposed groups. Randomization was stratified by body weight that produced similar group mean weights using Provantis^TM^, Version 6.5.0.1 software (Instem, Philadelphia, PA).

Due to the short duration of the study, disease screening was not conducted at the study laboratory; however, both rats and mice were obtained from commercial vendors with extensive health surveillance programs. Rats were obtained from a colony free of the following rat pathogens: Sendai virus, pneumonia virus of mice, sialodacryoadenitis virus, Kilham rat virus, Toolan’s H1 virus, rat minute virus, reovirus, rat theilovirus, lymphocytic choriomeningitis virus, hantavirus, mouse adenovirus, rat parvovirus, Mycoplasma pulmonis, and Pneumocystis carinii. Mice were obtained from a colony free of the following mouse pathogens: ectromelia virus, epizootic diarrhea of infant mice (EDIM), lymphocytic choriomeningitis virus, Mycoplasma pulmonis, mouse hepatitis virus, mouse norovirus, mouse parvovirus, minute virus of mice, pneumonia virus of mice, reovirus, Sendai, and Theiler's murine encephalomyelitis virus.

Groups of five male and five female rats and mice were provided Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl in drinking water for 15 days at the following exposure concentrations: Emim-Cl (0, 3, 10, 30, or 100 mg/mL), Bmim-Cl (0, 0.3, 1, or 3 mg/mL for rats; 0, 1, 3, or 6 mg/mL for mice), Bmpy-Cl (0, 1, 3, or 6 mg/mL for rats; 0, 3, 6, or 10 mg/mL for mice), or NBuPy-Cl (0, 1, 3, or 6 mg/mL). Groups of 10 male and 10 female rats and mice were provided tap water as the vehicle control.

Feed and water were available ad libitum. Rats and mice were housed individually (male mice) or five per cage by sex (male and female rats, female mice). Rats and mice were observed twice daily for signs of mortality or moribundity. Clinical observations and body weights were recorded initially, on study day 8, and at the end of the 2-week exposure period. Water consumption data were recorded on study days 1, 4, 8, 11, 14, and 15 for rats and study days 1, 5, 8, 12, and 15 for mice. Details of the study design and animal maintenance are summarized in Table 3. Information on feed composition and contaminants is provided in Appendix B.

Necropsies were performed on all rats and mice. Organ weights were determined for heart, right kidney, liver, lungs, right testis, and thymus. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes and Harderian gland, which were first fixed in Davidson’s solution), processed, and trimmed, embedded in paraffin, sectioned to a thickness of approximately 5 μm, and stained with hematoxylin and eosin (H&E). Complete histopathological examinations were performed by the study laboratory pathologist on all control animals and all animals in the highest exposed group for each IL. Table 3 lists the tissues and organs examined.

## Three-month Studies

### Study Design for Rats

Rats were approximately 3 to 5 weeks old on receipt. Animals were quarantined for 12 days and were approximately 5 to 7 weeks old on the first day of the studies. Rats were randomly assigned to one of four exposure groups for each IL. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Corporation, Lawrenceville, NJ).

Before the studies began, five male and five female rats were randomly selected for parasite evaluation and gross observation of disease. Additionally, the health of the animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of 10 male and 10 female rats were exposed to Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl in drinking water for 3 months at the following exposure concentrations: Emim-Cl (0, 1, 3, or 10 mg/mL), Bmim-Cl (0, 0.1, 0.3, or 1 mg/mL), Bmpy-Cl (0, 0.3 [males only], 1, 3, or 6 [females only] mg/mL), or NBuPy-Cl (0, 0.3, 1, or 3 mg/mL); tap water served as the control.

Feed and water were available ad libitum. Rats were housed up to three (males) or five (females) per cage. Details of the study design and animal maintenance are summarized in Table 4. Information on feed composition and contaminants is provided in Appendix B.

### Study Design for Mice

Mice were approximately 3 to 5 weeks old on receipt. Animals were quarantined for 12 days and were approximately 5 to 6 weeks old on the first day of the studies. Mice were randomly assigned to one of four exposure groups for each IL. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Corporation, Lawrenceville, NJ).

Before the studies began, five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. Additionally, the health of the animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of 10 male and 10 female mice were exposed to Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl in drinking water for 3 months at the following exposure concentrations: Emim-Cl (0, 3, 10, or 30 mg/mL), Bmim-Cl (0, 0.3, 1, or 3 mg/mL), Bmpy-Cl (0, 1, 3, 6 [females only], or 10 [males only] mg/mL), or NBuPy-Cl (0, 1, 3 or 6 mg/mL); tap water served as the control.

Feed and water were available ad libitum. Mice were housed individually (males) or up to four (females) per cage. Details of the study design and animal maintenance are summarized in Table 4. Information on feed composition and contaminants is provided in Appendix B.

### Clinical Examination and Pathology

During the 3-month studies, rats and mice were observed twice daily for signs of mortality or moribundity. Clinical observations and body weights were recorded initially, weekly, and at the end of the 3-month exposure period. Water consumption was measured weekly for 3 months.

Blood was collected from the retroorbital plexus (rats) or retroorbital sinus (mice) of all animals at the end of the 3-month exposure period for hematology, clinical chemistry (rats only), and erythrocyte micronuclei analyses. Animals were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Blood was collected into tubes containing ethylenediaminetetraacetic acid (EDTA) for hematology or into serum separator tubes for clinical chemistry. Hematology parameters were analyzed using the Advia^®^ 120 (Siemens Healthcare GmbH, Erlangen, Germany). Clinical chemistry parameters were analyzed using the Roche cobas^®^ c501 Chemistry Analyzer (Roche Diagnostics, Indianapolis, IN). The parameters measured are listed in Table 4.

At the end of the 3-month exposure period, samples were collected for sperm motility and vaginal cytology evaluations on all rats and mice. The parameters evaluated are listed in Table 4. For 16 consecutive days before the end of the 3-month exposure period, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were collected and subsequently stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Measured parameters of cycle length, number of cycles, and time spent in any specific stage of the estrous cycle of female rats and mice are reported in Appendix E. Male animals were evaluated for sperm count and motility. The right testis was used for organ weights and histopathology evaluation. The cauda portion of the left epididymis was used for sperm motility and concentration evaluation; the remainder of the left epididymis was fixed and processed for potential histopathological evaluation. The left testis was placed in a labeled plastic vial and then quick-frozen in dry ice for spermatid evaluation. Frozen testes were stored at approximately −70°C. However, due to artifacts identified during analysis (e.g., clumping of cells, too many sperm in sample), meaningful interpretation of motility and concentration data was not possible. Therefore, sperm motility and sperm/spermatid concentration data were not analyzed or reported.

Necropsies were performed on all animals. Organ weights were determined for the heart, right kidney, liver, lungs, right testis, and thymus from all rats and mice. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of approximately 5 μm, and stained with H&E. Complete histopathological examinations were performed by the study laboratory pathologist on all control animals and all animals in the highest exposed group for each IL. Table 4 lists the tissues and organs examined.

The laboratory report and select histopathology slides were reviewed by a quality assessment (QA) pathologist, who also served as the coordinator of the Pathology Working Group (PWG). The QA report and the reviewed slides were submitted to the NTP pathologist, who reviewed and addressed any inconsistencies in the diagnoses made by the study laboratory and QA pathologist. The QA/PWG pathologist presented representative histopathology slides containing examples of lesions related to test agent administration, examples of disagreements in diagnoses between the laboratory and QA pathologist, or lesions of general interest to the PWG for review. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^77^ and Boorman et al.^78^

## Statistical Methods

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. Fisher’s exact test,^79^ a procedure that uses the overall proportion of affected animals, was used to determine statistical significance between exposed and control animals, and the Cochran-Armitage trend test was used to test for significant trends.^80^

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^81^ and Williams.^82,83^ Hematology and clinical chemistry data, which typically have skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^84^ (as modified by Williams^85^ and Dunn^86^). The Jonckheere test^87^ was used to assess the significance of the exposure concentration-related trends and to determine whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test). Before statistical analysis, outliers identified by the Dixon and Massey^88^ test were examined by NTP personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis.

### Analysis of Vaginal Cytology Data

Vaginal cytology data consist of daily observations of estrous cycle stages over a 16-day period. Differences from the control group for cycle length and the number of cycles were analyzed using the Shirley and Dunn tests, as described above.

To identify disruptions in estrous cyclicity, a continuous-time Markov chain model (multistate model) was fit using a maximum likelihood approach,^89^ producing estimates of stage lengths for each exposure group. Confidence intervals for these estimates were obtained from bootstrap sampling of the individual animal cycle sequences. Stage lengths that were significantly different from the control animals were identified using permutation testing.

## Quality Assurance Methods

The 2-week and 3-month studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^90^ In addition, the 2-week and 3-month study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP toxicity report. Audit procedures and findings are presented in the reports and are on file at the NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this toxicity report.

## Genetic Toxicology

The genetic toxicities of Emim-Cl, Bmim-Cl, Bmpy-Cl, and NBuPy-Cl were assessed by testing whether each chemical induced mutations in various strains of Salmonella typhimurium and Escherichia coli or increased the frequency of micronucleated erythrocytes in rat and mouse peripheral blood. The protocol for these studies and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database that permits critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^91^ and the somatic mutation theory of cancer.^92,93^ Not all cancers, however, arise through genotoxic mechanisms.

### Bacterial Mutagenicity

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^94^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^95,96^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. Other tests, however, can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^97,98^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^99,100^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^101^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, determination of in vivo genetic effects is important to overall understanding of risks associated with exposure to a particular chemical.