# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-103

## E.1 1-Ethyl-3-Methylimidazolium Chloride (Emim-Cl)

### E.1.1 Two-week Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

### E.1.2 Two-week Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.1.3 Two-week Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

### E.1.4 Two-week Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.1.5 Three-month Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.1.6 Three-month Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

### E.1.7 Three-month Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.1.8 Three-month Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.2 1-Butyl-3-Methylimidazolium Chloride (Bmim-Cl)

### E.2.1 Two-week Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

### E.2.2 Two-week Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.2.3 Two-week Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

### E.2.4 Two-week Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.2.5 Three-month Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.2.6 Three-month Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

### E.2.7 Three-month Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.2.8 Three-month Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.3 1-Butyl-1-Methylpyrrolidinium Chloride (Bmpy-Cl)

### E.3.1 Two-week Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

### E.3.2 Two-week Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.3.3 Two-week Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P14 – Individual Animal Pathology Data

PA06 – Organ Weights Summary

### E.3.4 Two-week Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.3.5 Three-month Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.3.6 Three-month Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

### E.3.7 Three-month Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.3.8 Three-month Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.4 N-Butylpyridinium Chloride (NBuPy-Cl)

### E.4.1 Two-week Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

### E.4.2 Two-week Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.4.3 Two-week Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P14 – Individual Animal Pathology Data

PA06 – Organ Weights Summary

### E.4.4 Two-week Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

### E.4.5 Three-month Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.4.6 Three-month Individual Animal Data – Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

### E.4.7 Three-month Study Tables – Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E07 – Mean Water Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weight Summary

PA43 – Hematology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.4.8 Three-month Individual Animal Data – Mice

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## E.5 Genetic Toxicology

### E.5.1 1-Ethyl-3-Methylimidazolium Chloride Micronucleus Study in Sprague Dawley Rats

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.2 1-Ethyl-3-Methylimidazolium Chloride Micronucleus Study in B6C3F1 Mice

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.3 1-Ethyl-3-Methylimidazolium Chloride Ames Test

G06 Ames Summary Data

### E.5.4 1-Butyl-3-Methylimidazolium Chloride Micronucleus Study in Sprague Dawley Rats

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.5 1-Butyl-3-Methylimidazolium Chloride Micronucleus Study in B6C3F1 Mice

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.6 1-Butyl-3-Methylimidazolium Chloride Ames Test

G06 Ames Summary Data

### E.5.7 1-Butyl-1-Methylpyrrolidinium Chloride Micronucleus Study in Sprague Dawley Rats

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.8 1-Butyl-1-Methylpyrrolidinium Chloride Micronucleus Study in B6C3F1 Mice

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.9 1-Butyl-1-Methylpyrrolidinium Chloride Ames Test

G06 Ames Summary Data

### E.5.10 N-Butylpyridinium Chloride Micronucleus Study in Sprague Dawley Rats

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.11 N-Butylpyridinium Chloride Micronucleus Study in B6C3F1 Mice

G04 In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.5.12 N-Butylpyridinium Chloride Ames Test

G06 Ames Summary Data