# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table B-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4
Fish Meal (60% Protein) | 4
Corn Oil (without Preservatives) | 3
Soy Oil (without Preservatives) | 3
Dried Brewer’s Yeast | 1
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 μg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration in the Two-week Studies

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 13.74 | – | 1
Crude Fat (% by Weight) | 7.8 | – | 1
Crude Fiber (% by Weight) | 9.4 | – | 1
Ash (% by Weight) | 5.2 | – | 1
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.80 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.097 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.47–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.20 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.945 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.297 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 5,120 | | 1
Vitamin D (IU/kg)^a^ | 1,000 | – | –
α-Tocopherol (ppm) | 2,455 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^b^ | 6.5 | – | 1
Riboflavin (ppm) | 8.17 ± 2.84 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^b^ | 9.75 ± 2.05 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.9 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.887 | – | 1
Phosphorus (%) | 0.544 | – | 1
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21.0–73.1 | 29
Zinc (ppm) | 57.3 ± 25.55 | 43.3–184.0 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.017 ± 1.038 | 0.33–3.97 | 29
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 29

^a^ From formulation.

^b^ As hydrochloride.

Table B-4 Nutrient Composition of NTP-2000 Rat and Mouse Ration in the Three-month Studies of 1-Ethyl-3-Methylimidazolium Chloride

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.53 ± 0.435 | 13.9–14.9 | 4
Crude Fat (% by Weight) | 8.4 ± 0.082 | 8.3–8.5 | 4
Crude Fiber (% by Weight) | 9.34 ± 0.572 | 8.6–9.97 | 4
Ash (% by Weight) | 4.93 ± 0.149 | 4.79–5.14 | 4
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.80 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.097 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.297 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 3,620 ± 63.48 | 2,820–4,140 | 4
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 2,455 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^b^ | 7.2 ± 0.141 | 7.0–7.3 | 4
Riboflavin (ppm) | 8.17 ± 2.84 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^b^ | 9.75 ± 2.05 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.9 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.904 ± 0.033 | 0.867–0.947 | 4
Phosphorus (%) | 0.539 ± 0.020 | 0.51–0.553 | 4
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.55 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.017 ± 1.038 | 0.33–3.97 | 29
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 29

^a^ From formulation.

^b^ As hydrochloride.

Table B-5 Nutrient Composition of NTP-2000 Rat and Mouse Ration in the Three-month Studies of 1-Butyl-3-Methylimidazolium Chloride

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.43 ± 0.457 | 13.9–14.9 | 4
Crude Fat (% by Weight) | 8.38 ± 0.096 | 8.3–8.5 | 4
Crude Fiber (% by Weight) | 9.36 ± 0.570 | 8.6–9.97 | 4
Ash (% by Weight) | 4.99 ± 0.117 | 4.88–5.14 | 4
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.6–0.97 | 29
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.80 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.097 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.297 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 3,585 ± 654 | 2,820–4,140 | 4
Vitamin D (IU/kg)^a^ | 1,000 | – | –
α-Tocopherol (ppm) | 2,455 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^b^ | 7.3 ± 0.082 | 7.2–7.4 | 4
Riboflavin (ppm) | 8.17 ± 2.84 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^b^ | 9.75 ± 2.05 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.9 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.891 ± 0.017 | 0.867–0.905 | 4
Phosphorus (%) | 0.535 ± 0.018 | 0.51–0.53 | 4
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.55 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.017 ± 1.038 | 0.33–3.97 | 29
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 29

^a^ From formulation.

^b^ As hydrochloride.

Table B-6 Nutrient Composition of NTP-2000 Rat and Mouse Ration in the Three-month Studies of 1-Butyl-1-Methylpyrrolidinium Chloride

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.55 ± 0.532 | 13.9–15.2 | 4
Crude Fat (% by Weight) | 8.28 ± 0.320 | 7.8–8.5 | 4
Crude Fiber (% by Weight) | 9.48 ± 0.337 | 9.12–9.83 | 4
Ash (% by Weight) | 4.88 ± 0.132 | 4.79–5.07 | 4
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.80 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.097 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.297 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 3,443 ± 30.23 | 3,040–3,740 | 4
Vitamin D (IU/kg)^a^ | 1,000 | – | –
α-Tocopherol (ppm) | 2,455 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^b^ | 7.55 ±0.580 | 7.0–8.3 | 4
Riboflavin (ppm) | 8.17 ± 2.84 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^b^ | 9.75 ± 2.05 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.9 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.886 ± 0.138 | 0.697–1.02 | 4
Phosphorus (%) | 0.570 ± 0.030 | 0.553–0.615 | 4
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.55 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.017 ± 1.038 | 0.33–3.97 | 29
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 29

^a^ From formulation.

^b^ As hydrochloride.

Table B-7 Nutrient Composition of NTP-2000 Rat and Mouse Ration in the Three-month Studies of N-Butylpyridinium Chloride

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.43 ± 0.574 | 13.9–15.2 | 4
Crude Fat (% by Weight) | 8.1 ± 0.408 | 7.7–8.5 | 4
Crude Fiber (% by Weight) | 9.56 ± 0.308 | 9.12–9.83 | 4
Ash (% by Weight) | 4.91 ± 0.119 | 4.8–5.07 | 4
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.80 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.097 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.297 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 3,648 ± 48.61 | 3,040–4,220 | 4
Vitamin D (IU/kg)^a^ | 1,000 | – | –
α-Tocopherol (ppm) | 2,455 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^b^ | 7.5 ±0.648 | 6.8–8.3 | 4
Riboflavin (ppm) | 8.17 ± 2.84 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^b^ | 9.75 ± 2.05 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.9 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.902 ± 0.151 | 0.697–1.02 | 4
Phosphorus (%) | 0.580 ± 0.030 | 0.553–0.615 | 4
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.55 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.017 ± 1.038 | 0.33–3.97 | 29
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 29

^a^ From formulation.

^b^ As hydrochloride.

Table B-8 Contaminant Levels in NTP-2000 Rat and Mouse Ration in the Two-week Studies

| Level | Number of Samples
Contaminants
Arsenic (ppm) | 0.169 | 1
Cadmium (ppm) | 0.068 | 1
Lead (ppm) | 0.097 | 1
Mercury (ppm) | 0.022 | 1
Selenium (ppm) | 0.252 | 1
Aflatoxins (ppb)^a^ | <5.0 | 1
Nitrate Nitrogen (ppm)^b^ | 10 | 1
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | 1
BHA (ppm)^a,c^ | <1.00 | 1
BHT (ppm)^a,c^ | <1.00 | 1
Aerobic Plate Count (CFU/g) | <10.0 | 1
Coliform (MPN/g) | <3.0 | 1
Escherichia coli (MPN/g)^a^ | <10.0 | 1
Salmonella (MPN/g) | Negative | 1
Total Nitrosamines (ppb)^d^ | 11.3 | 1
N-Ndimethylamine (ppb)^d^ | 1.1 | 1
N-Npyrrolidine (ppb)^d^ | 10.2 | 1
Pesticides (ppm)
α-BHC^a^ | <0.01 | 1
β-BHC^a^ | <0.02 | 1
γ-BHC^a^ | <0.01 | 1
δ-BHC^a^ | <0.01 | 1
Heptachlor^a^ | <0.01 | 1
Aldrin^a^ | <0.01 | 1
Heptachlor Epoxide^a^ | <0.01 | 1
DDE^a^ | <0.01 | 1
DDD^a^ | <0.01 | 1
DDT^a^ | <0.01 | 1
HCB^a^ | <0.01 | 1
Mirex^a^ | <0.01 | 1
Methoxychlor^a^ | <0.05 | 1
Dieldrin^a^ | <0.01 | 1
Endrin^a^ | <0.01 | 1
Telodrin^a^ | <0.01 | 1
Chlordane^a^ | <0.05 | 1
Toxaphene^a^ | <0.10 | 1
Estimated PCBs^a^ | <0.20 | 1
Ronnel^a^ | <0.01 | 1
Ethion^a^ | <0.02 | 1
Trithion^a^ | <0.05 | 1
Diazinon^a^ | <0.10 | 1
Methyl Chlorpyrifos | 0.18 | 1
Methyl Parathion^a^ | <0.02 | 1
Ethyl Parathion^a^ | <0.02 | 1
Malathion | 0.0324 | 1
Endosulfan I^a^ | <0.01 | 1
Endosulfan II^a^ | <0.01 | 1
Endosulfane Sulfate^a^ | <0.03 | 1

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the level.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

Table B-9 Contaminant Levels in NTP-2000 Rat and Mouse Ration in the Three-month Studies of 1-Ethyl-3-Methylimidazolium Chloride

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.170 ± 0.023 | 0.143–0.192 | 4
Cadmium (ppm) | 0.047 ± 0.006 | 0.043–0.055 | 4
Lead (ppm) | 0.096 ± 0.030 | 0.066–0.122 | 4
Mercury (ppm) | 0.010 ± 0.001 | 0.01–0.011 | 4
Selenium (ppm) | 0.159 ± 0.003 | 0.155–0.162 | 4
Aflatoxins (ppb)^a^ | <5.0 | – | 4
Nitrate Nitrogen (ppm)^b^ | 14.23 ± 5.57 | 10.0–22.0 | 4
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 4
BHA (ppm)^a,c^ | <1.00 | – | 4
BHT (ppm)^a,c^ | <1.00 | – | 4
Aerobic Plate Count (CFU/g) | <10.0 | – | 4
Coliform (MPN/g) | <3.0 | – | 4
Escherichia coli (MPN/g)^a^ | <10.0 | – | 4
Salmonella (MPN/g) | Negative | – | 4
Total Nitrosamines (ppb)^d^ | 7.625 ± 2.082 | 5.4–9.04 | 4
N-Ndimethylamine (ppb)^d^ | 0.975 ± 1.127 | 0–2 | 4
N-Npyrrolidine (ppb)^d^ | 6.65 ± 0.995 | 5.4–7.5 | 4
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 4
β-BHC^a^ | <0.02 | – | 4
γ-BHC^a^ | <0.01 | – | 4
δ-BHC^a^ | <0.01 | – | 4
Heptachlor^a^ | <0.01 | – | 4
Aldrin^a^ | <0.01 | – | 4
Heptachlor Epoxide^a^ | <0.01 | – | 4
DDE^a^ | <0.01 | – | 4
DDD^a^ | <0.01 | – | 4
DDT^a^ | <0.01 | – | 4
HCB^a^ | <0.01 | – | 4
Mirex^a^ | <0.01 | – | 4
Methoxychlor^a^ | <0.05 | – | 4
Dieldrin^a^ | <0.01 | – | 4
Endrin^a^ | <0.01 | – | 4
Telodrin^a^ | <0.01 | – | 4
Chlordane^a^ | <0.05 | – | 4
Toxaphene^a^ | <0.10 | – | 4
Estimated PCBs^a^ | <0.20 | – | 4
Ronnel^a^ | <0.01 | – | 4
Ethion^a^ | <0.02 | – | 4
Trithion^a^ | <0.05 | – | 4
Diazinon^a^ | <0.10 | – | 4
Methyl Chlorpyrifos | 0.074 ± 0.055 | 0.02–0.015 | 4
Methyl Parathion^a^ | <0.02 | – | 4
Ethyl Parathion^a^ | <0.02 | – | 4
Malathion | 0.029 ± 0.014 | 0.02–0.05 | 4
Endosulfan I^a^ | <0.01 | – | 4
Endosulfan II^a^ | <0.01 | – | 4
Endosulfane Sulfate^a^ | <0.03 | – | 4

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

Table B-10 Contaminant Levels in NTP-2000 Rat and Mouse Ration in the Three-month Studies of 1-Butyl-3-Methylimidazolium Chloride

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.163 ± 0.021 | 0.143–0.192 | 4
Cadmium (ppm) | 0.046 ± 0.004 | 0.043–0.052 | 4
Lead (ppm) | 0.084 ± 0.025 | 0.066–0.121 | 4
Mercury (ppm) | 0.01 | 0.01–0.01 | 4
Selenium (ppm) | 0.155 ± 0.005 | 0.147–0.159 | 4
Aflatoxins (ppb)^a^ | <5.0 | – | 4
Nitrate Nitrogen (ppm)^b^ | 18.83 ± 8.29 | 10.0–28.8 | 4
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 4
BHA (ppm)^a,c^ | <1.00 | – | 4
BHT (ppm)^a,c^ | <1.00 | – | 4
Aerobic Plate Count (CFU/g) | <10.0 | – | 4
Coliform (MPN/g) | <3.0 | – | 4
Escherichia coli (MPN/g)^a^ | <10.0 | – | 4
Salmonella (MPN/g) | Negative | – | 4
Total Nitrosamines (ppb)^d^ | 6.125 ± 2.497 | 3.4–9.4 | 4
N-Ndimethylamine (ppb)^d^ | 0.65 ± 0.896 | 0.0–1.9 | 4
N-Npyrrolidine (ppb)^d^ | 5.475 ± 2.040 | 2.7–7.5 | 4
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 4
β-BHC^a^ | <0.02 | – | 4
γ-BHC^a^ | <0.01 | – | 4
δ-BHC^a^ | <0.01 | – | 4
Heptachlor^a^ | <0.01 | – | 4
Aldrin^a^ | <0.01 | – | 4
Heptachlor Epoxide^a^ | <0.01 | – | 4
DDE^a^ | <0.01 | – | 4
DDD^a^ | <0.01 | – | 4
DDT^a^ | <0.01 | – | 4
HCB^a^ | <0.01 | – | 4
Mirex^a^ | <0.01 | – | 4
Methoxychlor^a^ | <0.05 | – | 4
Dieldrin^a^ | <0.01 | – | 4
Endrin^a^ | <0.01 | – | 4
Telodrin^a^ | <0.01 | – | 4
Chlordane^a^ | <0.05 | – | 4
Toxaphene^a^ | <0.10 | – | 4
Estimated PCBs^a^ | <0.20 | – | 4
Ronnel^a^ | <0.01 | – | 4
Ethion^a^ | <0.02 | – | 4
Trithion^a^ | <0.05 | – | 4
Diazinon^a^ | <0.10 | – | 4
Methyl Chlorpyrifos | 0.065 ± 0.061 | 0.02–0.15 | 4
Methyl Parathion^a^ | <0.02 | – | 4
Ethyl Parathion^a^ | <0.02 | – | 4
Malathion | 0.0213 ± 0.003 | 0.02–0.025 | 4
Endosulfan I^a^ | <0.01 | – | 4
Endosulfan II^a^ | <0.01 | – | 4
Endosulfane Sulfate^a^ | <0.03 | – | 4

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

Table B-11 Contaminant Levels in NTP-2000 Rat and Mouse Ration in the Three-Month Studies of 1-Butyl-1-Methylpyrrolidinium Chloride

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.171 ± 0.023 | 0.149–0.196 | 4
Cadmium (ppm) | 0.052 ± 0.005 | 0.046–0.058 | 4
Lead (ppm) | 0.104 ± 0.020 | 0.078–0.122 | 4
Mercury (ppm) | 0.011 ± 0.001 | 0.01–0.011 | 4
Selenium (ppm) | 0.173 ± 0.01 | 0.162–0.186 | 4
Aflatoxins (ppb)^a^ | <5.0 | – | 4
Nitrate Nitrogen (ppm)^b^ | 22.38 ± 16.84 | 10–45.9 | 4
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 4
BHA (ppm)^a,c^ | <1.00 | – | 4
BHT (ppm)^a,c^ | <1.00 | – | 4
Aerobic Plate Count (CFU/g) | 46.25 ± 44.98 | 10–110 | 4
Coliform (MPN/g) | <3.0 | – | 4
Escherichia coli (MPN/g)^a^ | <10.0 | – | 4
Salmonella (MPN/g) | Negative | – | 4
Total Nitrosamines (ppb)^d^ | 9.9 ± 2.23 | 7.4–12.8 | 4
N-Ndimethylamine (ppb)^d^ | 2.175 ± 1.978 | 0–4.8 | 4
N-Npyrrolidine (ppb)^d^ | 7.725 ± 0.378 | 7.4–8.1 | 4
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 4
β-BHC^a^ | <0.02 | – | 4
γ-BHC^a^ | <0.01 | – | 4
δ-BHC^a^ | <0.01 | – | 4
Heptachlor^a^ | <0.01 | – | 4
Aldrin^a^ | <0.01 | – | 4
Heptachlor Epoxide^a^ | <0.01 | – | 4
DDE^a^ | <0.01 | – | 4
DDD^a^ | <0.01 | – | 4
DDT^a^ | <0.01 | – | 4
HCB^a^ | <0.01 | – | 4
Mirex^a^ | <0.01 | – | 4
Methoxychlor^a^ | <0.05 | – | 4
Dieldrin^a^ | <0.01 | – | 4
Endrin^a^ | <0.01 | – | 4
Telodrin^a^ | <0.01 | – | 4
Chlordane^a^ | <0.05 | – | 4
Toxaphene^a^ | <0.10 | – | 4
Estimated PCBs^a^ | <0.20 | – | 4
Ronnel^a^ | <0.01 | – | 4
Ethion^a^ | <0.02 | – | 4
Trithion^a^ | <0.05 | – | 4
Diazinon^a^ | <0.10 | – | 4
Methyl Chlorpyrifos | 0.058 ± 0.025 | 0.025–0.084 | 4
Methyl Parathion^a^ | <0.02 | – | 4
Ethyl Parathion^a^ | <0.02 | – | 4
Malathion | 0.090 ± 0.067 | 0.02–0.169 | 4
Endosulfan I^a^ | <0.01 | – | 4
Endosulfan II^a^ | <0.01 | – | 4
Endosulfane Sulfate^a^ | <0.03 | – | 4

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

Table B-12 Contaminant Levels in NTP-2000 Rat and Mouse Ration in the Three-month Studies of N-Butylpyridinium Chloride

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.179 ± 0.033 | 0.149–0.216 | 4
Cadmium (ppm) | 0.051 ± 0.005 | 0.046–0.058 | 4
Lead (ppm) | 0.101 ± 0.162 | 0.078–0.115 | 4
Mercury (ppm) | 0.010 ± 0.001 | 0.01–0.011 | 4
Selenium (ppm) | 0.171 ± 0.013 | 0.155–0.186 | 4
Aflatoxins (ppb)^a^ | <5.0 | – | 4
Nitrate Nitrogen (ppm)^b^ | 26.625 ± 5.57 | 10.0–45.9 | 4
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 4
BHA (ppm)^a,c^ | <1.00 | – | 4
BHT (ppm)^a,c^ | <1.00 | – | 4
Aerobic Plate Count (CFU/g) | 46.25 ± 44.98 | 10–110 | 4
Coliform (MPN/g) | <3.0 | – | 4
Escherichia coli (MPN/g)^a^ | <10.0 | – | 4
Salmonella (MPN/g) | Negative | – | 4
Total Nitrosamines (ppb)^d^ | 9.75 ± 2.29 | 7.4–12.8 | 4
N-Ndimethylamine (ppb)^d^ | 1.975 ± 2.040 | 0–4.8 | 4
N-Npyrrolidine (ppb)^d^ | 7.775 ± 0.330 | 7.4–8.1 | 4
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 4
β-BHC^a^ | <0.02 | – | 4
γ-BHC^a^ | <0.01 | – | 4
δ-BHC^a^ | <0.01 | – | 4
Heptachlor^a^ | <0.01 | – | 4
Aldrin^a^ | <0.01 | – | 4
Heptachlor Epoxide^a^ | <0.01 | – | 4
DDE^a^ | <0.01 | – | 4
DDD^a^ | <0.01 | – | 4
DDT^a^ | <0.01 | – | 4
HCB^a^ | <0.01 | – | 4
Mirex^a^ | <0.01 | – | 4
Methoxychlor^a^ | <0.05 | – | 4
Dieldrin^a^ | <0.01 | – | 4
Endrin^a^ | <0.01 | – | 4
Telodrin^a^ | <0.01 | – | 4
Chlordane^a^ | <0.05 | – | 4
Toxaphene^a^ | <0.10 | – | 4
Estimated PCBs^a^ | <0.20 | – | 4
Ronnel^a^ | <0.01 | – | 4
Ethion^a^ | <0.02 | – | 4
Trithion^a^ | <0.05 | – | 4
Diazinon^a^ | <0.10 | – | 4
Methyl Chlorpyrifos | 0.216 ± 0.315 | 0.025–0.686 | 4
Methyl Parathion^a^ | <0.02 | – | 4
Ethyl Parathion^a^ | <0.02 | – | 4
Malathion | 0.082 ± 0.074 | 0.02–0.169 | 4
Endosulfan I^a^ | <0.01 | – | 4
Endosulfan II^a^ | <0.01 | – | 4
Endosulfane Sulfate^a^ | <0.03 | – | 4

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.