# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Ionic Liquids

### A.1.1 1-Ethyl-3-Methylimidazolium Chloride (Emim-Cl)

1‐Ethyl‐3‐methylimidazolium chloride (Emim-Cl) was obtained from Sigma-Aldrich (St. Louis, MO) in three lots (S37784, S46787, and STBB3624). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO). Reports on analyses performed in support of the ionic liquid (IL) studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot S37784 of Emim-Cl was a faint yellow solid, lot S46787 was a brown solidified mass, and lot STBB3624 was a yellow-brown solid. The chemical identity was confirmed using infrared (IR) and ^1^H nuclear magnetic resonance (NMR) spectroscopies. The IR and ^1^H NMR spectra (Figure A-1, Figure A-2, Figure A-3) were consistent with reference spectra (SDBSWeb: https://sdbs.db.aist.go.jp, National Institute of Advanced Industrial Science and Technology, accessed November 1, 2010) and the anticipated structure of Emim-Cl. In addition, mass spectrometry (MS) and elemental analysis were performed to aid in chemical identity confirmation. Mass spectra supported the presence of the cation [Emim]^+^ at m/z 111.0 for lot S37784, m/z 111.1 for lot S46787, and m/z 111.0 for lot STBB3624. Elemental analysis was performed by Prevalere Life Sciences, Inc. (Whitesboro, NY). The relative amounts of carbon, hydrogen, nitrogen, and chlorine for lot S37784 (49.01%, 7.46%, 18.60%, and 24.17%), lot S46787 (49.17%, 7.82%, 18.81%, and 24.37%), and lot STBB3624 (47.27%, 7.86%, 17.66%, and 22.19%) were within 2% of the theoretical values.

The moisture content of lots S37784, S46787, and STBB3624 was determined by Karl Fischer titration. The purity profiles of the three lots were determined using high-performance liquid chromatography (HPLC) with evaporative light scattering detection (ELSD) and HPLC with ultraviolet (UV) detection. Chloride content of each lot was quantified using ion chromatography (IC). Weight loss on drying was attempted to determine volatile content, but constant weight of the test article could not be achieved due to its hygroscopic nature. The volatile content was determined by headspace gas chromatography (GC/headspace) with flame ionization detection (FID) for lot STBB3624.

For lot S37784, Karl Fischer titration yielded a water content of approximately 0.2%. This value is an estimate due to the hygroscopic nature of the compound. No impurities were detected in lot S37784 with HPLC/ELSD (Table A-1, System D). The IC analysis determined the chloride concentration for lot S37784 to be 23.80% ± 0.14(sd)% (sd = standard deviation) (Table A-1, System F). The overall purity of the lot was determined to be >99%. Lot S37784 was reanalyzed at 20 months after the first analysis using HPLC/UV (Table A-1, System B), and the purity was determined to be 99.0% ± 0.9(sd)%.

For lot S46787, Karl Fischer titration yielded a water content of approximately 0.6%. No impurities were detected in lot S46787 with HPLC/ELSD (Table A-1, System D). The IC analysis determined the chloride concentration for lot S46787 to be 23.50% ± 0.08(sd)% (Table A-1, System F). The overall purity of the test article was >99%.

For lot STBB3624, Karl Fischer titration yielded a water content of approximately 1.1%. No impurities were detected in lot STBB3624 with HPLC/ELSD (Table A-1, System C). The IC analysis determined the chloride concentration for lot STBB3624 to be 22.26% ± 0.33(sd)% (Table A-1, System G). The GC/headspace analysis for residual solvent content determined that acetonitrile, isopropanol, and ethyl acetate were not present at concentrations >0.001% (Table A-2, System H). The overall purity of the lot was determined to be >99%. The purity of lot STBB3624 was reevaluated prior to use in the 3-month study using HPLC/UV (Table A-1, System B) and determined to be 101.0% ± 0.5(sd)% relative to a frozen reference sample of the same lot.

Accelerated stability studies of Emim-Cl were conducted on samples of lot STBB3624 stored under an inert headspace in amber glass vials sealed with Teflon^®^-lined screw-top lids at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures. After 2 weeks, samples were analyzed by HPLC/UV (Table A-1, System B). Stability of the bulk chemical was confirmed for at least 2 weeks when stored under an inert headspace and protected from light at temperatures from −20°C to 60°C.

The two bottles of lot S37784 were completely melted and thoroughly blended. They were then transferred into amber glass bottles and sealed with an inert gas headspace and Teflon^®^-lined lids. A single drum of lot STBB3624 was completely melted, thoroughly blended, and transferred into wide-mouth amber glass bottles and sealed with an inert gas headspace and Teflon^®^-lined lids. All containers were then placed in two plastic bags with the outermost bag containing Drierite desiccant and stored under inert gas at room temperature.

### A.1.2 1-Butyl-3-Methylimidazolium Chloride (Bmim-Cl)

1-Butyl-3-methylimidazolium chloride (Bmim-Cl) was obtained from Solvent Innovations (Koln, Germany) in a single lot (99/787) and from Sigma-Aldrich (St. Louis, MO) in a single lot (STBB3444). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO). Reports on analyses performed in support of the IL studies are on file at NIEHS.

Lot 99/787 of Bmim-Cl was a pale amber solid in 1- to 4-inch pieces, and lot STBB3444 was a solid white mass with small orange streaks. The lot identities were confirmed using IR and ^1^H NMR spectroscopies. The IR and ^1^H NMR spectra (Figure A-4, Figure A-5, Figure A-6) were consistent with the proposed structure. No reference spectra were available for comparison. In addition, MS and elemental analysis were performed to aid in chemical identity confirmation. Mass spectra supported the presence of the cation [Bmim]^+^ at m/z 139.0 for lot 99/787 and m/z 139.1 for lot STBB3444. Elemental analysis was performed by Prevalere Life Sciences, Inc. (Whitesboro, NY). The relative amounts of carbon, hydrogen, nitrogen, and chlorine for lot 99/787 (54.64%, 8.91%, 15.83%, and 19.91%) and lot STBB3444 (53.72%, 8.71%, 14.98%, and 18.92%) were within 2% of the theoretical values.

The moisture content of lots 99/787 and STBB3444 was determined by Karl Fischer titration. The purity profiles of lots 99/787 and STBB3444 were determined using HPLC/ELSD and HPLC/UV, and the chloride content was quantified using IC. The volatile content was determined by GC/headspace with FID for lot STBB3444.

For lot 99/787, Karl Fischer titration yielded a water content of approximately 0.5%. This value is an estimate due to the hygroscopic nature of the compound. No impurities were detected in lot 99/787 with HPLC/ELSD (Table A-1, System C). The IC analysis determined the percent chloride concentration for lot 99/787 to be 20.01% ± 0.02(sd)% and detected no bromide (Table A-1, System G). Weight loss on drying was attempted to determine volatile content for lot 99/787, but constant weight of the test article could not be achieved due to its hygroscopic nature. The overall purity of lot 99/787 was determined to be >99%. Lot 99/787 was reanalyzed 26 months later using HPLC/UV (Table A-1, System B) and determined to be 98.6% ± 0.5( d- )% ( d- is the average deviation between two samples) relative to a frozen reference sample of the same lot.

For lot STBB3444, Karl Fischer titration yielded a water content of approximately 0.7%. No significant response was obtained from the test article with HPLC/UV detection at 240 nm (Table A-1, System A). No impurities ≥0.05% were detected in lot STBB3444 with HPLC/ELSD (Table A-1, System C). The IC analysis determined the percent chloride concentration for lot STBB3444 to be 19.28% ± 0.43(sd)% (Table A-1, System G). The GC/headspace analysis for residual solvent content determined that acetonitrile, isopropanol, and ethyl acetate were not present at concentrations >0.001% (Table A-2, System H). The overall purity of lot STBB3444 was determined to be >99%. The purity of lot STBB3444 was reevaluated prior to use in the 3-month study using HPLC/UV (Table A-1, System B) and determined to be 101.4% ± 2.0(sd)% relative to a frozen reference sample of the same lot.

Accelerated stability studies of Bmim-Cl were conducted on samples of lot STBB3444 stored under an inert headspace in amber glass vials sealed with Teflon^®^-lined screw-top lids at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures. After 2 weeks, samples were analyzed by HPLC/UV (Table A-1, System B). Stability of the bulk chemical was confirmed for at least 2 weeks when stored under an inert headspace and protected from light at temperatures from −20°C to 60°C.

Lot 99/787 was completely melted, thoroughly blended, and then stored in secondary containment under an inert atmosphere at room temperature. Lot STBB3444 also was completely melted and then thoroughly blended. After homogenization, it was transferred into wide-mouth amber glass bottles and sealed with an inert gas headspace and Teflon^®^-lined lids. All containers were then placed in two plastic bags with the outermost bag containing Drierite desiccant stored under inert gas at room temperature.

### A.1.3 1-Butyl-1-Methylpyrrolidinium Chloride (Bmpy-Cl)

1-Butyl-1-methylpyrrolidinium chloride (Bmpy-Cl) was obtained from Solvent Innovations (Koln, Germany) in a single lot (99/831) and from Promy Chemical, Inc. (El Sobrante, CA) in a single lot (20100610). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO). Reports on analyses performed in support of the IL studies are on file at NIEHS.

Lot 99/831 of Bmpy-Cl was a white chunky powder, and lot 20100610 was a pale-yellow crystalline powder. The chemical identity was confirmed using IR and ^1^H NMR spectroscopies. The IR and ^1^H NMR spectra (Figure A-7, Figure A-8, Figure A-9) were consistent with the proposed structure. No reference spectra were available for comparison. In addition, MS and elemental analysis were performed to confirm chemical identity. Mass spectra supported the presence of the cation [Bmpy]^+^ at m/z 141.9 for lot 99/831 and at m/z 142.1 for lot 20100610. Elemental analysis was performed by Prevalere Life Sciences, Inc. (Whitesboro, NY). The relative amounts of carbon, hydrogen, nitrogen, and chlorine for lot 99/831 (60.29%, 11.66%, 7.78%, and 19.97%) and lot 20100610 (60.43%, 11.26%, 7.50%, and 20.67%) were within 1% of the theoretical values.

The moisture content of lots 99/831 and 20100610 was determined by Karl Fischer titration, and the purity profiles of both lots were determined using HPLC/ELSD and HPLC with charged aerosol detection (CAD). Chloride content was quantified using IC. The volatile content was determined by weight loss on drying for lot 99/831 and GC/headspace with FID for lot 20100610.

For lot 99/831, Karl Fischer titration yielded a water content of approximately 0.5%. This value is an estimate due to the hygroscopic nature of the compound. No impurities were detected in lot 99/831 with HPLC/ELSD (Table A-1, System C). The IC analysis determined the percent chloride concentration for lot 99/831 to be 19.71% ± 0.27(sd)% and detected no bromide (Table A-1, System G). Weight loss on drying determined a volatile content for lot 99/831 of 0.75% ± 0.12( d- )% after 2 hours of drying. The overall purity of lot 99/831 was determined to be >99%. The purity of lot 99/831 was reevaluated prior to use in the 3-month study using HPLC/ELSD (Table A-1, System D) and determined to be 101.3% ± 1.2(sd)% relative to a frozen reference sample of the same lot.

For lot 20100610, Karl Fischer titration yielded a water content of approximately 1.2%. No impurities ≥0.05% were detected in lot 20100610 with HPLC/ELSD (Table A-1, System C). The IC analysis determined the chloride concentration for lot 20100610 to be 19.16% ± 0.65(sd)% (Table A-1, System G). The GC/headspace analysis for residual solvent content determined that acetonitrile, isopropanol, and ethyl acetate were not present at concentrations >0.001% (Table A-2, System H). The overall purity of lot 20100610 was determined to be >98%. The purity of lot 20100610 was reevaluated prior to use in the 3-month study using HPLC/CAD (Table A-1, System E) and determined to be 99.9% ± 0.3(sd)% relative to a frozen reference sample of the same lot.

Accelerated stability studies of Bmpy-Cl were conducted on samples of lot 20100610 stored under an inert headspace in amber glass vials sealed with Teflon^®^-lined screw-top lids at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures. After 2 weeks, samples were analyzed by HPLC/ELSD (Table A-1, System D). Stability of the bulk chemical was confirmed for at least 2 weeks when stored under an inert headspace and protected from light at temperatures from −20°C to 60°C.

Details of the homogenization of lot 99/831 were not reported. Lot 99/831 was stored at room temperature under inert gas. Lot 20100610 was manually blended by hand kneading the unopened Mylar bag containing the bulk material for 3 to 4 minutes. After homogenization, the material was transferred into wide-mouth amber glass bottles and sealed with an inert gas headspace and Teflon^®^-lined lids. All containers were then placed in two plastic bags with the outermost bag containing Drierite desiccant and stored at room temperature.

### A.1.4 N-Butylpyridinium Chloride (NBuPy-Cl)

N-Butylpyridinium chloride (NBuPy-Cl) was obtained from Solvent Innovations (Koln, Germany) in a single lot (99/830) and from Promy Chemical, Inc. (El Sobrante, CA) in a single lot (20100610). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO). Reports on analyses performed in support of the IL studies are on file at NIEHS.

Lot 99/830 of NBuPy-Cl was an off-white solid with a peach hue, and lot 20100610 was a pale-yellow crystalline powder. The chemical identity was confirmed using IR and ^1^H NMR spectroscopies. The IR and ^1^H NMR spectra (Figure A-10, Figure A-11, Figure A-12) were consistent with the proposed structure. No reference IR spectra were available for comparison; the ^1^H spectrum was consistent with a reference spectrum (SDBSWeb: https://sdbs.db.aist.go.jp, National Institute of Advanced Industrial Science and Technology, accessed November 1, 2010). In addition, MS and elemental analysis were performed to aid in chemical identity confirmation. Mass spectra supported the presence of the cation [NBuPy]^+^ at m/z 135.9 for lot 99/830 and at m/z 136.1 for lot 20100610. Elemental analysis was performed by Prevalere Life Sciences, Inc. (Whitesboro, NY). The relative amounts of carbon, hydrogen, nitrogen, and chlorine for lot 99/830 (62.75%, 8.31%, 7.99%, and 20.57%) and lot 20100610 (62.66%, 8.21%, 7.72%, and 20.49%) were within 1% of the theoretical values.

The moisture content of lots 99/830 and 20100610 was determined by Karl Fischer titration. The purity profiles of lots 99/830 and 20100610 were determined using HPLC/UV and HPLC/ELSD, and the chloride content was quantified using IC. The volatile content was determined by GC/headspace with FID for lot 20100610.

For lot 99/830, Karl Fischer titration yielded a water content of approximately 0.3%. This value is an estimate due to the hygroscopic nature of the compound. Purity of the test article with HPLC/UV was 99.23%, with one reportable impurity of 0.61% (Table A-1, System A). No impurities were detected in lot 99/830 with HPLC/ELSD (Table A-1, System C). The IC analysis determined the chloride concentration for lot 99/830 to be 20.47% ± 0.13(sd)% and detected no bromide (Table A-1, System G). Weight loss on drying was attempted to determine volatile content for lot 99/830, but constant weight of the test article could not be achieved due to its hygroscopic nature. The purity of lot 99/830 was reevaluated prior to use in the 3-month study using HPLC/UV (Table A-1, System B) and determined to be 101.1% ± 2.3(sd)% relative to a frozen reference sample of the same lot. The overall purity was >99%.

For lot 20100610, Karl Fischer titration yielded a water content of approximately 0.5%. Purity of the test article with HPLC/UV detection was 99.27%, with one impurity of 0.73% (Table A-1, System A). No impurities were detected in lot 20100610 with HPLC/ELSD (Table A-1, System C). The IC analysis determined the chloride concentration for lot 20100610 to be 20.25% ± 0.11(sd)% (Table A-1, System G). The GC/headspace analysis for residual solvent content detected six impurities using two procedures (Table A-2, System I, System J). Two of these were identified as methanol (<0.01%) and pyridine (0.3%). The test material was further analyzed for impurities with GC/MS (Table A-2, System K). Two more impurities were tentatively identified as ethyl ether and 1-chlorobutane on the basis of the observed mass spectra. The overall purity of the lot was determined to be >98%. The purity of lot 20100610 was reevaluated prior to use in the 3-month study using HPLC/UV (Table A-1, System B) and determined to be 100.6% ± 0.7(sd)% relative to a frozen reference sample of the same lot.

Accelerated stability studies of NBuPy-Cl were conducted on samples of lot 20100610 stored under an inert headspace in amber glass vials sealed with Teflon^®^-lined screw-top lids at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures. After 2 weeks, samples were analyzed by HPLC/UV (Table A-1, System B). Stability of the bulk chemical was confirmed for at least 2 weeks when stored under an inert headspace and protected from light at temperatures from −20°C to 60°C.

Lot 99/830 was blended manually by shaking the bottle vigorously prior to opening to ensure homogeneity and was stored under inert gas at room temperature. The original bulk material in a Mylar bag (containing inner Mylar bags) of lot 20100610 was manually blended for 3 to 4 minutes by hand kneading the unopened bag. After homogenization, the bulk material of lot 20100610 was transferred into wide-mouth amber glass bottles and sealed with an inert gas headspace and Teflon^®^-lined lids. All containers were then placed in two plastic bags with the outermost bag containing Drierite desiccant and stored at room temperature.

## A.2 Preparation and Analysis of Dose Formulations

### A.2.1 Two-week Studies

The dose formulations for the 2-week study were prepared once at MRIGlobal (Kansas City, MO) by mixing Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl with tap water to give the required concentrations (Table A-3). Dose formulations of Emim-Cl were prepared at concentrations of 3, 10, and 30 mg/mL with lot S37784 and 100 mg/mL with a combination of lots S37784 and S46787. Dose formulations of Bmim-Cl were prepared at concentrations of 0.3, 1, 3, and 6 mg/mL with lot 99/787. Dose formulations of Bmpy-Cl were prepared at concentrations of 1, 3, 6, and 10 mg/mL with lot 99/831. Dose formulations of NBuPy-Cl were prepared at concentrations of 0, 1, 3, and 6 mg/mL with lot 99/830. All dose formulations were stored protected from light at refrigerated temperatures (2°C–8°C) for up to 7 days until shipment to the study laboratory (BioReliance, Rockville, MD). At the study laboratory, all dose formulations were stored protected from light in a plastic carboy at refrigerated temperatures (2°C–8°C) and used within 42 days.

The homogeneity and stability of the dose formulations for lots S37784 (Emim-Cl), 99/787 (Bmim-Cl), 99/831 (Bmpy-Cl), and 99/830 (NBuPy-Cl) were determined by the analytical laboratory using HPLC/UV or HPLC/ELSD (Table A-1, Systems B, B, D, and B, respectively). Homogeneity was confirmed for the highest and lowest dose formulations of each ionic liquid. Dose formulations were considered stable if the measured concentrations were statistically no different from day 0 concentrations using the test variability limit statistical analysis. The storage stability of the 3 mg/mL Emim-Cl dose formulation was confirmed when protected from light for ≤35 days at room temperature, ≤21 days under refrigeration, and for ≤7 days under simulated animal room temperature. Storage stability of 0.3 mg/mL Bmim-Cl and 1 mg/mL Bmpy-Cl dose formulations were confirmed for ≤42 days at room and refrigerated temperatures and for ≤7 days under simulated animal room conditions. The storage stability of 1 mg/mL NBuPy-Cl dose formulation was confirmed for ≤35 days at room and refrigerated temperatures and for ≤4 days under simulated animal room conditions.

Analyses of preadministration and postadministration dose formulations for the 2-week studies of Emim-Cl, Bmim-Cl, and NBuPy-Cl were conducted once for each study by MRIGlobal analytical chemistry laboratory using HPLC/UV (Table A-1, System B). HPLC/ELSD (Table A-1, System D) was used to conduct analysis of preadministration and postadministration dose formulations of Bmpy-Cl. Postadministration dose formulation analysis results are averages from animal room drinking water bottles and bulk containers. All dose formulations were within 10% of the target concentrations for all four chemicals (Emim-Cl [Table A-5], Bmim-Cl [Table A-8], Bmpy-Cl [Table A-11], and NBuPy-Cl [Table A-14]). The pH of Emim-Cl and Bmpy-Cl dose formulations were measured postadministration and are reported in Table A-17 and Table A-18, respectively.

### A.2.2 Three-month Studies

The dose formulations for the 3-month studies were prepared at the Battelle study laboratory (Columbus, OH) by mixing Emim-Cl, Bmim-Cl, Bmpy-Cl, or NBuPy-Cl with tap water to give the required concentrations for each species (Table A-4). Dose formulations of Emim-Cl were prepared at four concentrations of 0, 1, 3, and 10 mg/mL for the rat study and 0, 3, 10, and 30 mg/mL for the mouse study with lot STBB3624. Dose formulations of Bmim-Cl were prepared at four concentrations of 0, 0.1, 0.3, and 1 mg/mL for the rat study and 0, 0.3, 1, and 3 mg/mL for the mouse study with lot STBB3444. Dose formulations of Bmpy-Cl were prepared at five concentrations of 0, 0.3, 1, 3, and 6 mg/mL for the rat study and 0, 1, 3, 6, and 10 mg/mL for the mouse study with lot 20100610. Dose formulations of NBuPy-Cl were prepared at four concentrations of 0, 0.3, 1, and 3 mg/mL for the rat study and 0, 1, 3, and 6 mg/mL for the mouse study with lot 20100610. The formulations were stored protected from light in a plastic carboy at refrigerated temperatures (2°C–8°C). Emim-Cl and NBuPy-Cl formulations were used within 35 days of preparation, and Bmim-Cl and Bmpy-Cl formulations were used within 42 days of preparation.

The storage stability of 1 mg/mL Emim-Cl, 0.1 mg/mL Bmim-Cl, and 0.3 mg/mL NBuPy-Cl dose formulations at refrigerated and room temperatures were analyzed by the study laboratory using HPLC/UV (Table A-1, System B). HPLC/CAD (Table A-1, System E) was used to conduct similar analyses of 0.3 mg/mL Bmpy-Cl dose formulations. Dose formulations were considered stable if the measured concentrations were within 10% of the day 0 concentrations and no signs of degradation were detected in the chromatograms. All four IL dose formulations were considered stable for ≤42 days when stored refrigerated or at room temperature, protected from light.

Analyses of preadministration and postadministration dose formulations for the 3-month studies of Emim-Cl, Bmim-Cl, and NBuPy-Cl were conducted once after each new formulation preparation at the Battelle study laboratory using HPLC/UV (Table A-1, System B). HPLC/CAD (Table A-1, System E) was used to conduct similar analyses of the dose formulations for the 3-month study of Bmpy-Cl. All preadministration dose formulations for all four chemicals were within 10% of the target concentrations. All animal room samples for Emim-Cl (Table A-6, Table A-7) and Bmim-Cl (Table A-9, Table A-10) were within 10% of the target concentrations. All animal room samples for Bmpy-Cl (Table A-12, Table A-13) were within 10% of the target concentrations, with the exception of three samples for the rat study and five samples for the mouse study. For the rat study, one 0.3 mg/mL formulation was 14.0% and 15.8% above target for the animal room and carboy samples, respectively, and one 1 mg/mL formulation was 10.7% above target for the carboy sample. For the mouse study, two 10 mg/mL formulations were 11.7% and 12.3% above target in the animal room and 13.7% and 14.3% above target in the carboys. Additionally, one 1 mg/mL formulation was 10.7% above target for the carboy sample. All animal room samples for NBuPy-Cl (Table A-15, Table A-16) were within 10% of the target concentrations, with the exception of one carboy sample for the rat study, which was 13.1% above the target concentration of 0.3 mg/mL.

Table A-1 Liquid and Ion Chromatography Systems Used in the Two-week and Three-month Drinking Water Studies of Ionic Liquids

Chromatography | Detection System | Column | Mobile Phase
High-performance Liquid Chromatography Systems
System A
High-performance liquid chromatography | Ultraviolet (240 nm) | Supelco Discovery Cyano (150 mm × 4.6 mm ID, 5 μm particle size) | A: Acetonitrile B: Aqueous ~33 mM ammonium acetate, acidified with acetic acid to pH ~4.0 Gradient program: A:B Isocratic 85:15, 0.8 mL/min flow rate
System B
High-performance liquid chromatography | Ultraviolet (210 nm) | Supelco Discovery Cyano (150 mm × 4.6 mm ID, 5 μm particle size) | A: Acetonitrile B: Aqueous ~40 mM ammonium acetate with 0.5% acetic acid Gradient program: A:B Isocratic 90:10, 0.8–1.0 mL/min flow rate
System C
High-performance liquid chromatography | Evaporative light scattering | Supelco Discovery Cyano (150 mm × 4.6 mm ID, 5 μm particle size) | A: Acetonitrile B: Aqueous ~33 mM ammonium acetate, acidified with acetic acid to pH ~4.0 Gradient program: A:B Isocratic 85:15, 0.8 mL/min flow rate
System D
High-performance liquid chromatography | Evaporative light scattering | Supelco Discovery Cyano (150 mm × 4.6 mm ID, 5 μm particle size) | A: Acetonitrile B: Aqueous ~40 mM ammonium acetate, acidified with 0.5% acetic acid Gradient program: A:B Isocratic 90:10, 0.8–1.0 mL/min flow rate
System E
High-performance liquid chromatography | Charged aerosol detector | Supelco Discovery Cyano (150 mm × 4.6 mm ID, 5 μm particle size) | A: Acetonitrile B: ~40 mM Ammonium acetate with 0.5% acetic acid Gradient program: A:B Isocratic 90:10, 0.8 mL/min flow rate
Ion Chromatography Systems
System F
Ion chromatography | Conductivity | Transgenomic ICSep AN2 (250 mm × 4.6 mm ID) | Mobile Phase: Aqueous ~3.2 mM sodium carbonate and ~1.0 mM sodium bicarbonate, 1 mL/min flow rate External Water: ~0.5% Aqueous sulfuric acid, 4 mL/min flow rate
System G
Ion chromatography | Conductivity | Transgenomic ICSep AN2 (250 mm × 4.6 mm ID) with Transgenomic ICSep AN2 Guard (50 mm × 4.6 mm ID) | Mobile Phase: Aqueous ~3.2 mM sodium carbonate and ~1.0 mM sodium bicarbonate, 1 mL/min flow rate External Water: ~0.5% Aqueous sulfuric acid, 4 mL/min flow rate

ID = internal diameter.

Table A-2 Gas Chromatography Systems Used in the Two-week and Three-month Drinking Water Studies of Ionic Liquids

Detection System | Column | Carrier Gas | Oven Temperature Program
System H
Flame ionization (260°C) | Phenomenex Zebron ZB-624 (30 m × 0.53 mm ID, 3.0-μm film thickness) | Helium, 2.55 mL/min | 50°C for 6 min, then 8°C/min to 210°C, held for 4 min
System I
Flame ionization (250°C) | Rxi624SilMS (30 m × 0.32 mm ID, 1.8-μm film thickness) | Helium, 2.37 mL/min | 40°C for 20 min, then 10°C/min to 240°C, held for 20 min
System J
Flame ionization (250°C) | Stabilwax (30 m × 0.32 mm ID, 0.25-μm film thickness) | Helium, 2.46 mL/min | 50°C for 20 min, then 6°C/min to 165°C, held for 20 min
System K
Electron ionization mass spectrometry | Rxi-624Sil mS (30 m × 0.32 mm ID, 1.8-μm film thickness) | Helium, 3.3 mL/min | 40°C for 20 min, then 10°C/min to 240°C, held for 20 min

ID = internal diameter.

Table A-3 Preparation and Storage of Dose Formulations in the Two-week Drinking Water Studies of Ionic Liquids

Emim-Cl | Bmim-Cl | Bmpy-Cl | NBuPy-Cl
Preparation
The appropriate amount of test article was weighed and transferred into a 1-L volumetric flask. The contents were diluted to volume with tap water and mixed by inversion. The formulation was transferred to a 10-L plastic carboy. After using the same volumetric flask to weigh and transfer nine additional 1-L aliquots to the carboy, the 10-L formulation was mixed well. The doses were prepared once.
Chemical Lot Number
S37784 and S46787^a^ | 99/787 | 99/831 | 99/830
Maximum Storage Time^b^
42 days
Storage Conditions
Plastic carboys covered with aluminum foil. Stored refrigerated at 2°C–8°C.
Analytical Laboratory
MRIGlobal (Kansas City MO)
Study Laboratory
BioReliance (Rockville, Maryland)

Emim-Cl = 1-ethyl-3-methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

^a^ Lot S37784 was used for the 3, 10, and 30 mg/mL formulations. Lots S37784 and S46787 were combined to make the 100 mg/mL formulation.

^b^ The expiration date used for all formulations. Emim-Cl and NBuPy-Cl were determined to be stable when refrigerated for up to 21 days and 35 days, respectively, in the stability study conducted before the 2-week study. All formulations were determined to be stable when refrigerated for up to 42 days during the stability study conducted before the 3-month study.

Table A-4 Preparation and Storage of Dose Formulations in the Three-month Drinking Water Studies of Ionic Liquids

Emim-Cl | Bmim-Cl | Bmpy-Cl | NBuPy-Cl
Preparation
An appropriate amount of vehicle (tap water) was added to the container holding the preweighed test article. The container was sealed, shaken, and mixed by sonication and/or vortexing until the contents were a solution. The solution was then transferred into a plastic carboy containing approximately half the required amount of vehicle. The test article container was rinsed with vehicle at least three times, and the rinses were transferred into the carboy. Approximately 90% of the final total vehicle volume was added to the carboy, and the formulation was stirred with an overhead stirrer. Approximately 200 mL was dispensed through the spigot into a beaker and poured back into the carboy. The beaker was rinsed with vehicle thoroughly, and the rinse was added into the carboy. The carboy was diluted to final volume with vehicle. The formulation was stirred with an overhead stirrer.
Chemical Lot Number
STBB3624 | STBB3444 | 20100610 | 20100610
Maximum Storage Time
35 days | 42 days | 42 days | 35 days
Storage Conditions
Plastic carboys stored refrigerated at 2°C–8°C.
Study Laboratory
Battelle (Columbus, OH)

Emim-Cl = 1-ethyl-3-methylimidazolium chloride; Bmim-Cl = 1-butyl-3-methylimidazolium chloride; Bmpy-Cl = 1-butyl-1-methylpyrrolidinium chloride; NBuPy-Cl = n-butylpyridinium chloride.

Table A-5 Results of Analyses of Dose Formulations Administered to Male and Female Rats and Mice in the Two-week Drinking Water Studies of 1-Ethyl-3-Methylimidazolium Chloride

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^b^ | Difference from Target (%)
February 26, 2009 | March 4, 2009 | 3 | 3.0 ± 0.03 | −0.4
February 26, 2009 | March 4, 2009 | 10 | 10.1 ± 0.1 | 1.2
February 26, 2009 | March 4, 2009 | 30 | 30.8 ± 0.2 | 2.8
February 26, 2009 | March 4, 2009 | 100 | 100.6 ± 0.9 | 0.6
Animal Room Samples (Rats)^c^
February 26, 2009 | April 2, 2009 | 3 | 3.0 ± 0.0 | −0.8
February 26, 2009 | April 2, 2009 | 10 | 10.0 ± 0.0 | −0.2
February 26, 2009 | April 2, 2009 | 30 | 30.5 ± 0.2 | 1.6
February 26, 2009 | April 2, 2009 | 100 | 100.1 ± 0.4 | 0.1
Animal Room Samples (Mice)^c^
February 26, 2009 | April 2, 2009 | 3 | 3.0 ± 0.0 | −1.5
February 26, 2009 | April 2, 2009 | 10 | 10.0 ± 0.0 | −0.3
February 26, 2009 | April 2, 2009 | 30 | 30.3 ± 0.1 | 1.2
February 26, 2009 | April 2, 2009 | 100 | 100.1 ± 0.6 | 0.1

^a^ Analysis dates assumed from laboratory report dates. Preadministration formulations were analyzed in triplicate within 1 week of preparation.

^b^ Average and standard deviation of all sample measurements.

^c^ Preadministration samples were taken from carboys. Postadministration samples were taken from carboys and drinking water bottles.

Table A-6 Results of Analyses of Dose Formulations Administered to Male and Female Rats in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
April 19, 2013 | April 19, 2013 | 0 | BLOQ | NA
April 19, 2013 | April 19, 2013 | 1 | 0.999 ± 0.002 | −0.1
April 19, 2013 | April 19, 2013 | 3 | 2.97 ± 0.01 | −0.9
April 19, 2013 | April 19, 2013 | 10 | 10.2 ± 0.1 | 2.3
June 4, 2013 | June 6, 2013 | 0 | BLOQ | NA
June 4, 2013 | June 6, 2013 | 1 | 1.00 ± 0.01 | 0.2
June 4, 2013 | June 6, 2013 | 3 | 3.04 ± 0.00 | 1.3
June 4, 2013 | June 6, 2013 | 10 | 10.0 ± 0.1 | 0.3
July 15, 2013 | July 16, 2013 | 0 | BLOQ | NA
July 15, 2013 | July 16, 2013 | 1 | 0.992 ± 0.002 | −0.8
July 15, 2013 | July 16, 2013 | 3 | 2.93 ± 0.01 | −2.5
July 15, 2013 | July 16, 2013 | 10 | 10.1 ± 0.1 | 0.7
Animal Room Samples
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 0 | BLOQ | NA
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 1 | 1.03 ± 0.00 | 3.0
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 3 | 3.03 ± 0.01 | 0.9
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 10 | 10.2 ± 0.1 | 2.3
April 19, 2013 (Carboy) | May 24, 2013 | 0 | BLOQ | NA
April 19, 2013 (Carboy) | May 24, 2013 | 1 | 1.03 ± 0.0 | 3.0
April 19, 2013 (Carboy) | May 24, 2013 | 3 | 3.03 ± 0.01 | 1.1
April 19, 2013 (Carboy) | May 24, 2013 | 10 | 10.3 ± 0.1 | 2.7
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 0 | BLOQ | NA
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 1 | 0.998 ± 0.002 | –0.2
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 3 | 3.03 ± 0.01 | 1.1
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 10 | 10.2 ± 0.1 | 1.7
June 4, 2013 (Carboy) | July 9, 2013 | 0 | BLOQ | NA
June 4, 2013 (Carboy) | July 9, 2013 | 1 | 0.986 ± 0.009 | –1.4
June 4, 2013 (Carboy) | July 9, 2013 | 3 | 2.99 ± 0.01 | −0.2
June 4, 2013 (Carboy) | July 9, 2013 | 10 | 10.0 ± 0.1 | 0.4
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 0 | BLOQ | NA
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 1 | 0.996 ± 0.007 | −0.4
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 3 | 2.95 ± 0.01 | −1.5
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 10 | 10.2 ± 0.0 | 2.0
July 15, 2013 (Carboy) | August 9, 2013 | 0 | BLOQ | NA
July 15, 2013 (Carboy) | August 9, 2013 | 1 | 1.01 ± 0.01 | 1.0
July 15, 2013 (Carboy) | August 9, 2013 | 3 | 2.98 ± 0.02 | −0.7
July 15, 2013 (Carboy) | August 9, 2013 | 10 | 10.2 ± 0.1 | 1.7

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.001 mg/mL.

Table A-7 Results of Analyses of Dose Formulations Administered to Male and Female Mice in the Three-month Drinking Water Study of 1-Ethyl-3-Methylimidazolium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
April 19, 2013 | April 19, 2013 | 0 | BLOQ | NA
April 19, 2013 | April 19, 2013 | 3 | 2.97 ± 0.01 | −0.9
April 19, 2013 | April 19, 2013 | 10 | 10.2 ± 0.1 | 2.3
April 19, 2013 | April 19, 2013 | 30 | 30.4 ± 0.1 | 1.4
June 4, 2013 | June 6, 2013 | 0 | BLOQ | NA
June 4, 2013 | June 6, 2013 | 3 | 3.04 ± 0.00 | 1.3
June 4, 2013 | June 6, 2013 | 10 | 10.0 ± 0.1 | 0.3
June 4, 2013 | June 6, 2013 | 30 | 30.2 ± 0.2 | 0.7
July 15, 2013 | July 16, 2013 | 0 | BLOQ | NA
July 15, 2013 | July 16, 2013 | 3 | 2.93 ± 0.01 | −2.5
July 15, 2013 | July 16, 2013 | 10 | 10.1 ± 0.1 | 0.7
July 15, 2013 | July 16, 2013 | 30 | 30.0 ± 0.1 | 0
Animal Room Samples
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 0 | BLOQ | NA
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 3 | 3.04 ± 0.00 | 1.3
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 10 | 10.2 ± 0.1 | 1.7
April 19, 2013 (Drinking Water Bottle) | May 24, 2013 | 30 | 31.3 ± 0.1 | 4.2
April 19, 2013 (Carboy) | May 24, 2013 | 0 | BLOQ | NA
April 19, 2013 (Carboy) | May 24, 2013 | 3 | 3.03 ± 0.01 | 1.1
April 19, 2013 (Carboy) | May 24, 2013 | 10 | 10.3 ± 0.1 | 2.7
April 19, 2013 (Carboy) | May 24, 2013 | 30 | 31.1 ± 0.1 | 3.7
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 0 | BLOQ | NA
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 3 | 2.99 ± 0.01 | −0.5
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 10 | 10.1 ± 0.1 | 0.7
June 4, 2013 (Drinking Water Bottle) | July 9, 2013 | 30 | 29.6 ± 0.2 | −1.4
June 4, 2013 (Carboy) | July 9, 2013 | 0 | BLOQ | NA
June 4, 2013 (Carboy) | July 9, 2013 | 3 | 2.99 ± 0.01 | −0.2
June 4, 2013 (Carboy) | July 9, 2013 | 10 | 10.0 ± 0.1 | 0.4
June 4, 2013 (Carboy) | July 9, 2013 | 30 | 29.3 ± 0.1 | −2.3
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 0 | BLOQ | NA
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 3 | 2.93 ± 0.01 | −2.2
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 10 | 10.2 ± 0.0 | 2
July 15, 2013 (Drinking Water Bottle) | August 9, 2013 | 30 | 30.2 ± 0.2 | 0.6
July 15, 2013 (Carboy) | August 9, 2013 | 0 | BLOQ | NA
July 15, 2013 (Carboy) | August 9, 2013 | 3 | 2.98 ± 0.02 | −0.7
July 15, 2013 (Carboy) | August 9, 2013 | 10 | 10.2 ± 0.1 | 1.7
July 15, 2013 (Carboy) | August 9, 2013 | 30 | 30.1 ± 0.0 | 0.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.001 mg/mL.

Table A-8 Results of Analyses of Dose Formulations Administered to Male and Female Rats and Mice in the Two-week Drinking Water Studies of 1-Butyl-3-Methylimidazolium Chloride

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^b^ | Difference from Target (%)
February 25, 2009 | February 25, 2009 | 0.3 | 0.3 ± 0.0 | 5.1
February 25, 2009 | February 25, 2009 | 1 | 1.0 ± 0.0 | 1.8
February 25, 2009 | February 25, 2009 | 3 | 3.1 ± 0.0 | 3.0
February 25, 2009 | February 25, 2009 | 6 | 6.2 ± 0.1 | 3.1
Animal Room Samples (Rats)^c^
February 25, 2009 | April 6, 2009 | 0.3 | 0.3 ± 0.0 | 2.8
February 25, 2009 | April 6, 2009 | 1 | 1.0 ± 0.0 | 0.0
February 25, 2009 | April 6, 2009 | 3 | 3.0 ± 0.0 | 1.0
February 25, 2009 | April 6, 2009 | 6 | NA | NA
Animal Room Samples (Mice)^c^
February 25, 2009 | April 6, 2009 | 0.3 | NA | NA
February 25, 2009 | April 6, 2009 | 1 | 1.0 ± 0.0 | −0.3
February 25, 2009 | April 6, 2009 | 3 | 3.0 ± 0.0 | 0.9
February 25, 2009 | April 6, 2009 | 6 | 5.9 ± 0.2 | −2.1

NA = not applicable.

^a^ Analysis dates assumed from laboratory report dates. Preadministration formulations were analyzed in triplicate within 1 week of preparation.

^b^ Average and standard deviation of all sample measurements.

^c^ Preadministration samples were taken from carboys. Postadministration samples were taken from carboys and drinking water bottles.

Table A-9 Results of Analyses of Dose Formulations Administered to Male and Female Rats in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
April 15, 2013 | April 16, 2013 | 0 | BLOQ | NA
April 15, 2013 | April 16, 2013 | 0.1 | 0.0989 ± 0.0003 | −1.1
April 15, 2013 | April 16, 2013 | 0.3 | 0.306 ± 0.000 | 2.0
April 15, 2013 | April 16, 2013 | 1 | 0.999 ± 0.001 | −0.1
May 6, 2013 | May 7, 2013 | 0 | BLOQ | NA
May 6, 2013 | May 7, 2013 | 0.1 | 0.0981 ± 0.0006 | −1.9
May 6, 2013 | May 7, 2013 | 0.3 | 0.302 ± 0.000 | 0.7
May 6, 2013 | May 7, 2013 | 1 | 1.02 ± 0.00 | 2.0
June 17, 2013 | June 17, 2013 | 0 | BLOQ | NA
June 17, 2013 | June 17, 2013 | 0.1 | 0.102 ± 0.001 | 1.7
June 17, 2013 | June 17, 2013 | 0.3 | 0.307 ± 0.001 | 2.2
June 17, 2013 | June 17, 2013 | 1 | 1.03 ± 0.01 | 3.3
Animal Room Samples
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 0 | BLOQ | NA
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 0.1 | 0.0991 ± 0.0001 | −0.9
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 0.3 | 0.312 ± 0.000 | 4.0
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 1 | 1.02 ± 0.00 | 2.0
April 15, 2013 (Carboy) | May 17, 2013 | 0 | BLOQ | NA
April 15, 2013 (Carboy) | May 17, 2013 | 0.1 | 0.0993 ± 0.0002 | −0.7
April 15, 2013 (Carboy) | May 17, 2013 | 0.3 | 0.311 ± 0.001 | 3.5
April 15, 2013 (Carboy) | May 17, 2013 | 1 | 1.02 ± 0.01 | 1.7
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 0 | BLOQ | NA
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 0.1 | 0.0953 ± 0.0005 | −4.7
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 0.3 | 0.301 ± 0.001 | 0.2
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 1 | 0.997 ± 0.001 | −0.3
May 6, 2013 (Carboy) | June 7, 2013 | 0 | BLOQ | NA
May 6, 2013 (Carboy) | June 7, 2013 | 0.1 | 0.0951 ± 0.0003 | −4.9
May 6, 2013 (Carboy) | June 7, 2013 | 0.3 | 0.300 ± 0.000 | 0.0
May 6, 2013 (Carboy) | June 7, 2013 | 1 | 0.994 ± 0.002 | −0.6
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 0 | BLOQ | NA
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 0.1 | 0.108 ± 0.001 | 7.7
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 0.3 | 0.329 ± 0.003 | 9.6
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 1 | 1.08 ± 0.01 | 8.3
June 17, 2013 (Carboy) | July 26, 2013 | 0 | BLOQ | NA
June 17, 2013 (Carboy) | July 26, 2013 | 0.1 | 0.106 ± 0.001 | 6.3
June 17, 2013 (Carboy) | July 26, 2013 | 0.3 | 0.325 ± 0.001 | 8.5
June 17, 2013 (Carboy) | July 26, 2013 | 1 | 1.08 ± 0.00 | 8.0

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.003 mg/mL.

Table A-10 Results of Analyses of Dose Formulations Administered to Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-3-Methylimidazolium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
April 15, 2013 | April 16, 2013 | 0 | BLOQ | NA
April 15, 2013 | April 16, 2013 | 0.3 | 0.306 ± 0.000 | 2.0
April 15, 2013 | April 16, 2013 | 1 | 0.999 ± 0.001 | −0.1
April 15, 2013 | April 16, 2013 | 3 | 2.92 ± 0.00 | −2.7
May 6, 2013 | May 7, 2013 | 0 | BLOQ | NA
May 6, 2013 | May 7, 2013 | 0.3 | 0.302 ± 0.000 | 0.7
May 6, 2013 | May 7, 2013 | 1 | 1.02 ± 0.00 | 2.0
May 6, 2013 | May 7, 2013 | 3 | 3.06 ± 0.0 | 2.0
June 17, 2013 | June 17, 2013 | 0 | BLOQ | NA
June 17, 2013 | June 17, 2013 | 0.3 | 0.307 ± 0.001 | 2.2
June 17, 2013 | June 17, 2013 | 1 | 1.03 ± 0.01 | 3.3
June 17, 2013 | June 17, 2013 | 3 | 3.14 ± 0.00 | 4.7
Animal Room Samples
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 0 | BLOQ | NA
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 0.3 | 0.309 ± 0.001 | 2.9
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 1 | 1.02 ± 0.00 | 2.0
April 15, 2013 (Drinking Water Bottle) | May 17, 2013 | 3 | 2.97 ± 0.01 | −0.9
April 15, 2013 (Carboy) | May 17, 2013 | 0 | BLOQ | NA
April 15, 2013 (Carboy) | May 17, 2013 | 0.3 | 0.311 ± 0.001 | 3.5
April 15, 2013 (Carboy) | May 17, 2013 | 1 | 1.02 ± 0.01 | 1.7
April 15, 2013 (Carboy) | May 17, 2013 | 3 | 2.98 ± 0.00 | −0.7
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 0 | BLOQ | NA
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 0.3 | 0.304 ± 0.000 | 1.3
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 1 | 1.00 ± 0.00 | 0.0
May 6, 2013 (Drinking Water Bottle) | June 7, 2013 | 3 | 2.99 ± 0.01 | −0.5
May 6, 2013 (Carboy) | June 7, 2013 | 0 | BLOQ | NA
May 6, 2013 (Carboy) | June 7, 2013 | 0.3 | 0.300 ± 0.000 | 0.0
May 6, 2013 (Carboy) | June 7, 2013 | 1 | 0.994 ± 0.002 | −0.6
May 6, 2013 (Carboy) | June 7, 2013 | 3 | 2.98 ± 0.00 | −0.7
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 0 | BLOQ | NA
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 0.3 | 0.306 ± 0.000 | 2.0
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 1 | 1.02 ± 0.00 | 2.0
June 17, 2013 (Drinking Water Bottle) | July 26, 2013 | 3 | 3.11 ± 0.01 | 3.5
June 17, 2013 (Carboy) | July 26, 2013 | 0 | BLOQ | NA
June 17, 2013 (Carboy) | July 26, 2013 | 0.3 | 0.325 ± 0.001 | 8.5
June 17, 2013 (Carboy) | July 26, 2013 | 1 | 1.08 ± 0.00 | 8.0
June 17, 2013 (Carboy) | July 26, 2013 | 3 | 3.12 ± 0.00 | 4.0

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.003 mg/mL.

Table A-11 Results of Analyses of Dose Formulations Administered to Male and Female Rats and Mice in the Two-week Drinking Water Studies of 1-Butyl-1-Methylpyrrolidinium Chloride

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^b^ | Difference from Target (%)
February 24, 2009 | March 2, 2009 | 1 | 1.1 ± 0.0 | 5.6
February 24, 2009 | March 2, 2009 | 3 | 3.3 ± 0.0 | 10.0
February 24, 2009 | March 2, 2009 | 6 | 6.4 ± 0.1 | 7.1
February 24, 2009 | March 2, 2009 | 10 | 10.3 ± 0.1 | 3.2
Animal Room Samples (Rats)^c^
February 24, 2009 | April 6, 2009 | 1 | 1.1 ± 0.0 | 5.6
February 24, 2009 | April 6, 2009 | 3 | 3.3 ± 0.0 | 9.4
February 24, 2009 | April 6, 2009 | 6 | 6.5 ± 0.1 | 8.1
February 24, 2009 | April 6, 2009 | 10 | NA | NA
Animal Room Samples (Mice)^c^
February 24, 2009 | April 6, 2009 | 1 | NA | NA
February 24, 2009 | April 6, 2009 | 3 | 3.3 ± 0.0 | 9.1
February 24, 2009 | April 6, 2009 | 6 | 6.3 ± 0.1 | 5.6
February 24, 2009 | April 6, 2009 | 10 | 10.2 ± 0.1 | 2.2

NA = not applicable.

^a^ Analysis dates assumed from laboratory report dates. Preadministration formulations were analyzed in triplicate within 1 week of preparation.

^b^ Average and standard deviation of all sample measurements.

^c^ Preadministration samples were taken from carboys. Postadministration samples were taken from carboys and drinking water bottles.

Table A-12 Results of Analyses of Dose Formulations Administered to Male and Female Rats in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
August 5, 2013 | August 7, 2013 | 0 | BLOQ | NA
August 5, 2013 | August 7, 2013 | 0.3 | 0.292 ± 0.003 | −2.7
August 5, 2013 | August 7, 2013 | 1 | 1.05 ± 0.01 | 5.3
August 5, 2013 | August 7, 2013 | 3 | 3.08 ± 0.01 | 2.5
August 5, 2013 | August 7, 2013 | 6 | 6.09 ± 0.08 | 1.5
September 25, 2013 | September 26, 2013 | 0 | BLOQ | NA
September 25, 2013 | September 26, 2013 | 0.3 | 0.297 ± 0.003 | −0.9
September 25, 2013 | September 26, 2013 | 1 | 1.03 ± 0.00 | 3.0
September 25, 2013 | September 26, 2013 | 3 | 3.14 ± 0.02 | 4.6
September 25, 2013 | September 26, 2013 | 6 | 6.07 ± 0.01 | 1.2
October 18, 2013 | October 21, 2013 | 0 | BLOQ | NA
October 18, 2013 | October 21, 2013 | 0.3 | 0.293 ± 0.011 | −2.2
October 18, 2013 | October 21, 2013 | 1 | 1.02 ± 0.00 | 2.0
October 18, 2013 | October 21, 2013 | 3 | 3.06 ± 0.05 | 2.1
October 18, 2013 | October 21, 2013 | 6 | 6.05 ± 0.09 | 0.8
Animal Room Samples
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 0 | BLOQ | NA
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 0.3 | 0.299 ± 0.001 | −0.5
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 1 | 1.03 ± 0.00 | 3.0
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 3 | 2.96 ± 0.02 | −1.2
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 6 | 5.97 ± 0.03 | −0.5
August 5, 2013 (Carboy) | September 13, 2013 | 0 | BLOQ | NA
August 5, 2013 (Carboy) | September 13, 2013 | 0.3 | 0.301 ± 0.003 | 0.2
August 5, 2013 (Carboy) | September 13, 2013 | 1 | 1.04 ± 0.01 | 4.3
August 5, 2013 (Carboy) | September 13, 2013 | 3 | 3.01 ± 0.03 | 0.3
August 5, 2013 (Carboy) | September 13, 2013 | 6 | 5.86 ± 0.08 | −2.4
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 0 | BLOQ | NA
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 0.3 | 0.342 ± 0.002 | 14
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 1 | 1.08 ± 0.01 | 7.7
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 3 | 3.13 ± 0.02 | 4.4
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 6 | 6.30 ± 0.02 | 5.0
September 25, 2013 (Carboy) | November 4, 2013 | 0 | BLOQ | NA
September 25, 2013 (Carboy) | November 4, 2013 | 0.3 | 0.347 ± 0.001 | 15.8
September 25, 2013 (Carboy) | November 4, 2013 | 1 | 1.06 ± 0.01 | 6.3
September 25, 2013 (Carboy) | November 4, 2013 | 3 | 3.15 ± 0.04 | 5.1
September 25, 2013 (Carboy) | November 4, 2013 | 6 | 6.31 ± 0.02 | 5.2
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 0 | BLOQ | NA
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 0.3 | 0.317 ± 0.001 | 5.8
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 1 | 1.09 ± 0.00 | 9.0
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 3 | 3.18 ± 0.05 | 5.9
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 6 | 6.57 ± 0.03 | 9.6
October 18, 2013 (Carboy) | November 22, 2013 | 0 | BLOQ | NA
October 18, 2013 (Carboy) | November 22, 2013 | 0.3 | 0.321 ± 0.006 | 7.1
October 18, 2013 (Carboy) | November 22, 2013 | 1 | 1.11 ± 0.01 | 10.7
October 18, 2013 (Carboy) | November 22, 2013 | 3 | 3.24 ± 0.03 | 7.9
October 18, 2013 (Carboy) | November 22, 2013 | 6 | 6.55 ± 0.04 | 9.1

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.002 mg/mL.

Table A-13 Results of Analyses of Dose Formulations Administered to Male and Female Mice in the Three-month Drinking Water Study of 1-Butyl-1-Methylpyrrolidinium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
August 5, 2013 | August 7, 2013 | 0 | BLOQ | NA
August 5, 2013 | August 7, 2013 | 1 | 1.05 ± 0.01 | 5.3
August 5, 2013 | August 7, 2013 | 3 | 3.08 ± 0.01 | 2.5
August 5, 2013 | August 7, 2013 | 6 | 6.09 ± 0.08 | 1.5
August 5, 2013 | August 7, 2013 | 10 | 10.5 ± 0.2 | 5.3
September 25, 2013 | September 26, 2013 | 0 | BLOQ | NA
September 25, 2013 | September 26, 2013 | 1 | 1.03 ± 0.00 | 3.0
September 25, 2013 | September 26, 2013 | 3 | 3.14 ± 0.02 | 4.6
September 25, 2013 | September 26, 2013 | 6 | 6.07 ± 0.01 | 1.2
September 25, 2013 | September 26, 2013 | 10 | 10.7 ± 0.1 | 6.7
October 18, 2013 | October 21, 2013 | 0 | BLOQ | NA
October 18, 2013 | October 21, 2013 | 1 | 1.02 ± 0.00 | 2.0
October 18, 2013 | October 21, 2013 | 3 | 3.06 ± 0.05 | 2.1
October 18, 2013 | October 21, 2013 | 6 | 6.05 ± 0.09 | 0.8
October 18, 2013 | October 21, 2013 | 10 | 10.6 ± 0.1 | 6.3
Animal Room Samples
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 0 | BLOQ | NA
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 1 | 1.02 ± 0.01 | 2.3
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 3 | 2.97 ± 0.01 | −1.0
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 6 | 6.06 ± 0.07 | 0.9
August 5, 2013 (Drinking Water Bottle) | September 13, 2013 | 10 | 10.4 ± 0.0 | 4.0
August 5, 2013 (Carboy) | September 13, 2013 | 0 | BLOQ | NA
August 5, 2013 (Carboy) | September 13, 2013 | 1 | 1.04 ± 0.01 | 4.3
August 5, 2013 (Carboy) | September 13, 2013 | 3 | 3.01 ± 0.03 | 0.3
August 5, 2013 (Carboy) | September 13, 2013 | 6 | 5.86 ± 0.08 | −2.4
August 5, 2013 (Carboy) | September 13, 2013 | 10 | 10.2 ± 0.1 | 2.3
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 0 | BLOQ | NA
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 1 | 1.08 ± 0.01 | 8.0
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 3 | 3.15 ± 0.02 | 5.1
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 6 | 6.19 ± 0.07 | 3.2
September 25, 2013 (Drinking Water Bottle) | November 4, 2013 | 10 | 11.2 ± 0.1 | 11.7
September 25, 2013 (Carboy) | November 4, 2013 | 0 | BLOQ | NA
September 25, 2013 (Carboy) | November 4, 2013 | 1 | 1.06 ± 0.01 | 6.3
September 25, 2013 (Carboy) | November 4, 2013 | 3 | 3.15 ± 0.04 | 5.1
September 25, 2013 (Carboy) | November 4, 2013 | 6 | 6.31 ± 0.02 | 5.2
September 25, 2013 (Carboy) | November 4, 2013 | 10 | 11.4 ± 0.1 | 13.7
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 0 | BLOQ | NA
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 1 | 1.07 ± 0.01 | 7.3
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 3 | 3.11 ± 0.06 | 3.7
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 6 | 6.36 ± 0.05 | 5.9
October 18, 2013 (Drinking Water Bottle) | November 22, 2013 | 10 | 11.2 ± 0.1 | 12.3
October 18, 2013 (Carboy) | November 22, 2013 | 0 | BLOQ | NA
October 18, 2013 (Carboy) | November 22, 2013 | 1 | 1.11 ± 0.01 | 10.7
October 18, 2013 (Carboy) | November 22, 2013 | 3 | 3.24 ± 0.03 | 7.9
October 18, 2013 (Carboy) | November 22, 2013 | 6 | 6.55 ± 0.04 | 9.1
October 18, 2013 (Carboy) | November 22, 2013 | 10 | 11.4 ± 0.1 | 14.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.002 mg/mL.

Table A-14 Results of Analyses of Dose Formulations Administered to Male and Female Rats and Mice in the Two-week Drinking Water Studies of N-Butylpyridinium Chloride

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^b,c^ | Difference from Target (%)
February 23, 2009 | February 23, 2009 | 0 | BLOQ | NA
February 23, 2009 | February 23, 2009 | 1 | 1.0 ± 0.0 | 1.6
February 23, 2009 | February 23, 2009 | 3 | 3.0 ± 0.0 | −0.9
February 23, 2009 | February 23, 2009 | 6 | 6.0 ± 0.1 | −0.3
Animal Room Samples (Rats)^c^
February 23, 2009 | April 2, 2009 | 0 | BLOQ | NA
February 23, 2009 | April 2, 2009 | 1 | 1.0 ± 0.0 | 0.0
February 23, 2009 | April 2, 2009 | 3 | 3.0 ± 0.0 | –0.3
February 23, 2009 | April 2, 2009 | 6 | 6.0 ± 0.0 | 0.0
Animal Room Samples (Mice)^d^
February 23, 2009 | April 2, 2009 | 0 | BLOQ | NA
February 23, 2009 | April 2, 2009 | 1 | 1.0 ± 0.0 | −0.4
February 23, 2009 | April 2, 2009 | 3 | 3.0 ± 0.0 | –0.2
February 23, 2009 | April 2, 2009 | 6 | 6.0 ± 0.0 | 0.2

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Analysis dates assumed from laboratory report dates. Preadministration formulations were analyzed in triplicate within 1 week of preparation.

^b^ Average and standard deviation of all sample measurements.

^c^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.03080 mg/mL.

^d^ Preadministration samples were taken from carboys. Postadministration samples were taken from carboys and drinking water bottles.

Table A-15 Results of Analyses of Dose Formulations Administered to Male and Female Rats in the Three-month Drinking Water Study of N-Butylpyridinium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
September 3, 2013 | September 3, 2013 | 0 | BLOQ | NA
September 3, 2013 | September 3, 2013 | 0.3 | 0.297 ± 0.001 | −1.0
September 3, 2013 | September 3, 2013 | 1 | 1.02 ± 0.01 | 1.7
September 3, 2013 | September 3, 2013 | 3 | 3.09 ± 0.02 | 2.9
October 11, 2013 | October 14, 2013 | 0 | BLOQ | NA
October 11, 2013 | October 14, 2013 | 0.3 | 0.310 ± 0.002 | 3.2
October 11, 2013 | October 14, 2013 | 1 | 1.07 ± 0.00 | 7.0
October 11, 2013 | October 14, 2013 | 3 | 3.04 ± 0.02 | 1.4
November 25, 2013 | December 2, 2013 | 0 | BLOQ | NA
November 25, 2013 | December 2, 2013 | 0.3 | 0.300 ± 0.005 | 0.1
November 25, 2013 | December 2, 2013 | 1 | 1.01 ± 0.01 | 0.7
November 25, 2013 | December 3, 2013 | 3 | 3.04 ± 0.02 | 1.5
Animal Room Samples
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 0 | BLOQ | NA
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 0.3 | 0.305 ± 0.002 | 1.6
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 1 | 1.02 ± 0.01 | 2.3
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 3 | 3.06 ± 0.02 | 2.1
September 3, 2013 (Carboy) | October 4, 2013 | 0 | BLOQ | NA
September 3, 2013 (Carboy) | October 4, 2013 | 0.3 | 0.306 ± 0.002 | 2.1
September 3, 2013 (Carboy) | October 4, 2013 | 1 | 1.03 ± 0.00 | 3.0
September 3, 2013 (Carboy) | October 4, 2013 | 3 | 3.07 ± 0.02 | 2.5
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 0 | BLOQ | NA
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 0.3 | 0.300 ± 0.001 | 0.0
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 1 | 1.03 ± 0.01 | 2.7
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 3 | 3.07 ± 0.00 | 2.3
October 11, 2013 (Carboy) | November 6, 2013 | 0 | BLOQ | NA
October 11, 2013 (Carboy) | November 6, 2013 | 0.3 | 0.301 ± 0.002 | 0.2
October 11, 2013 (Carboy) | November 6, 2013 | 1 | 1.05 ± 0.02 | 4.7
October 11, 2013 (Carboy) | November 6, 2013 | 3 | 3.09 ± 0.04 | 2.9
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 0 | BLOQ | NA
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 0.3 | 0.328 ± 0.004 | 9.4
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 1 | 1.03 ± 0.00 | 3.0
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 3 | 3.07 ± 0.02 | 2.3
November 25, 2013 (Carboy) | December 19, 2013 | 0 | BLOQ | NA
November 25, 2013 (Carboy) | December 19, 2013 | 0.3 | 0.339 ± 0.001 | 13.1
November 25, 2013 (Carboy) | December 19, 2013 | 1 | 1.03 ± 0.00 | 3.0
November 25, 2013 (Carboy) | December 19, 2013 | 3 | 3.05 ± 0.01 | 1.6

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.00130 mg/mL.

Table A-16 Results of Analyses of Dose Formulations Administered to Male and Female Mice in the Three-month Drinking Water Study of N-Butylpyridinium Chloride

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a,b^ | Difference from Target (%)
September 3, 2013 | September 3, 2013 | 0 | BLOQ | NA
September 3, 2013 | September 3, 2013 | 1 | 1.02 ± 0.01 | 1.7
September 3, 2013 | September 3, 2013 | 3 | 3.09 ± 0.02 | 2.9
September 3, 2013 | September 3, 2013 | 6 | 6.23 ± 0.03 | 3.8
October 11, 2013 | October 14, 2013 | 0 | BLOQ | NA
October 11, 2013 | October 14, 2013 | 1 | 1.07 ± 0.00 | 7.0
October 11, 2013 | October 14, 2013 | 3 | 3.04 ± 0.02 | 1.4
October 11, 2013 | October 14, 2013 | 6 | 6.06 ± 0.01 | 1.1
November 25, 2013 | December 2, 2013 | 0 | BLOQ | NA
November 25, 2013 | December 2, 2013 | 1 | 1.01 ± 0.01 | 0.7
November 25, 2013 | December 3, 2013 | 3 | 3.04 ± 0.02 | 1.5
November 25, 2013 | December 3, 2013 | 6 | 5.89 ± 0.25 | −1.9
Animal Room Samples
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 0 | BLOQ | NA
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 1 | 1.02 ± 0.00 | 2.0
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 3 | 3.03 ± 0.08 | 1.0
September 3, 2013 (Drinking Water Bottle) | October 4, 2013 | 6 | 6.21 ± 0.04 | 3.5
September 3, 2013 (Carboy) | October 4, 2013 | 0 | BLOQ | NA
September 3, 2013 (Carboy) | October 4, 2013 | 1 | 1.03 ± 0.00 | 3.0
September 3, 2013 (Carboy) | October 4, 2013 | 3 | 3.07 ± 0.02 | 2.5
September 3, 2013 (Carboy) | October 4, 2013 | 6 | 6.27 ± 0.01 | 4.6
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 0 | BLOQ | NA
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 1 | 1.03 ± 0.0l | 3.3
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 3 | 3.11 ± 0.02 | 3.8
October 11, 2013 (Drinking Water Bottle) | November 6, 2013 | 6 | 6.16 ± 0.03 | 2.7
October 11, 2013 (Carboy) | November 6, 2013 | 0 | BLOQ | NA
October 11, 2013 (Carboy) | November 6, 2013 | 1 | 1.05 ± 0.02 | 4.7
October 11, 2013 (Carboy) | November 6, 2013 | 3 | 3.09 ± 0.04 | 2.9
October 11, 2013 (Carboy) | November 6, 2013 | 6 | 6.13 ± 0.04 | 2.2
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 0 | BLOQ | NA
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 1 | 1.01 ± 0.00 | 1.0
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 3 | 3.01 ± 0.01 | 0.4
November 25, 2013 (Drinking Water Bottle) | December 19, 2013 | 6 | 6.00 ± 0.03 | −0.1
November 25, 2013 (Carboy) | December 19, 2013 | 0 | BLOQ | NA
November 25, 2013 (Carboy) | December 19, 2013 | 1 | 1.03 ± 0.00 | 3.0
November 25, 2013 (Carboy) | December 19, 2013 | 3 | 3.05 ± 0.01 | 1.6
November 25, 2013 (Carboy) | December 19, 2013 | 6 | 6.03 ± 0.07 | 0.4

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average and standard deviation of triplicate analysis.

^b^ The limit of quantification of the analytical method, estimated as 10 times the standard deviation of the lowest vehicle standard, was 0.00130 mg/mL.

Table A-17 Results of pH Analyses of Dose Formulations Administered to Male and Female Rats and Mice in the Two-week Drinking Water Studies of 1-Ethyl-3-Methylimidazolium Chloride

Target Concentration (mg/mL) | Species | Precipitate Observed in One or More Samples | Average pH Across Measured Samples^a^
3 | Rats | No | 8.7 ± 0.3
10 | Rats | No | 8.1 ± 0.0
30 | Rats | No | 7.3 ± 0.4
100 | Rats | No | 7.1 ± 0.0
3 | Mice | No | 8.3 ± 0.3
10 | Mice | No | 7.9 ± 0.1
30 | Mice | No | 7.7 ± 0.1
100 | Mice | No | 7.1 ± 0.0

^a^ Average and standard deviation of triplicate analysis.

Table A-18 Results of pH Analyses of Dose Formulations Administered to Male and Female Rats and Mice in the Two-week Drinking Water Studies of 1-Butyl-1-Methylpyrrolidinium Chloride

Target Concentration (mg/mL) | Species | Precipitate Observed in One or More Samples | Average pH Across Measured Samples^a^
1 | Rats | No | 9.1 ± 0.5
3 | Rats | No | 8.4 ± 0.1
6 | Rats | No | 8.5 ± 0.3
3 | Mice | Yes | 8.3 ± 0.1
6 | Mice | Yes | 8.5 ± 0.1
10 | Mice | Yes | 8.9 ± 0.3

^a^ Average and standard deviation of triplicate analysis.

Figure A-1

Infrared Absorption Spectrum of 1-Ethyl-3-Methylimidazolium Chloride (Lot S37784), Nujol Mineral Oil

Figure A-2

Infrared Absorption Spectrum of 1-Ethyl-3-Methylimidazolium Chloride (Lot STBB3624), Neat

Figure A-3

^1^H Nuclear Magnetic Resonance Spectrum of 1-Ethyl-3-Methylimidazolium Chloride (Lot S37784)

Figure A-4

Infrared Absorption Spectrum of 1-Butyl-3-Methylimidazolium Chloride (Lot STBB3444), Nujol Mineral Oil

Figure A-5

Infrared Absorption Spectrum of 1-Butyl-3-Methylimidazolium Chloride (Lot STBB3444), Neat

Figure A-6

^1^H Nuclear Magnetic Resonance Spectrum of 1-Butyl-3-Methylimidazolium Chloride (Lot STBB3444)

Figure A-7

Infrared Absorption Spectrum of 1-Butyl-1-Methylpyrrolidinium Chloride (Lot 20100610), Nujol Mineral Oil

Figure A-8

Infrared Absorption Spectrum of 1-Butyl-1-Methylpyrrolidinium Chloride (Lot 20100610), Neat

Figure A-9

^1^H Nuclear Magnetic Resonance Spectrum of 1-Butyl-1-Methylpyrrolidinium Chloride (Lot 20100610)

Figure A-10

Infrared Absorption Spectrum of N-Butylpyridinium Chloride (Lot 99/830), Nujol Mineral Oil

Figure A-11

Infrared Absorption Spectrum of N-Butylpyridinium Chloride (Lot 20100610), Neat

Figure A-12

^1^H Nuclear Magnetic Resonance Spectrum of N-Butylpyridinium Chloride (Lot 99/830)