# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-102

Report Series: NTP Toxicity Report Series

Report Series Number: 102

Official citation: National Toxicology Program (NTP). 2021. NTP technical report on the toxicity studies of trans-resveratrol (CASRN 501-36-0) administered by gavage for two weeks or three months to F344/NTac rats, Wister Han [Crl:WI(Han)] rats, and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 102.