# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicity Studies of Trans-resveratrol (CASRN 501-36-0) Administered by Gavage for Two Weeks or Three Months to F344/NTac Rats, Wistar Han [Crl:WI(Han)] Rats, and B6C3F1/N Mice by letter in March and April 2021 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicity Studies of Trans-resveratrol.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Devon Andres, Ph.D., DABT
  Biologist
  Biomedical Advanced Research Development Authority
  Washington, District of Columbia, USA
- Kevin Pearson, Ph.D.
  Professor, Department of Pharmacology and Nutritional Sciences
  University of Kentucky College of Medicine
  Lexington, Kentucky, USA