# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  M.C. Huang, Ph.D., Study Scientist
  S.A. Elmore, D.V.M., M.S., Study Pathologist
  C.R. Blystone, Ph.D.
  B.J. Collins, M.S.
  M.C. Cora, D.V.M.
  D. Germolec, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  C.A. Colleton, D.V.M.
  R.R. Dalefield, Ph.D.
  L.M. Fomby, D.V.M., Ph.D.
  K.A.B. Knostman, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Conducted prestart chemistry activities and dose formulations
  W.M. Black, B.S.
  B.L. Burback, Ph.D.
  K.A. Carrico, B.A.
  D.A. Contos, M.S.
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted preliminary chemistry activities, dose formulations, and biological sample chemistry analyses
  R.A. Fernando, Ph.D., Principal Investigator
  J.C. Blake, B.A.
  S.D. Cooper, M.S.
  J.W. Lodge, M.A.
  M. Silinski, Ph.D.
- Provided sperm count and vaginal cytology evaluation (SCVCE) analysis
  C.S. Sloan, M.S.
  R.W. Tyl, Ph.D.
- Pathology Associates, Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Review on rats and mice (3-month studies) (January 13, 2011)
  C.L. Johnson, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  E.T. Adams, D.V.M., Ph.D. (Mice)
  R.R. Moore, D.V.M., Ph.D. (Rats)