# References

1 ChemSpider. Structure search. 2021. https://www.chemspider.com/StructureSearch.aspx
2 Fritzemeier KH, Kindl H. Coordinate induction by UV-light of stillbene synthase phenylalanine ammonia-lyase and cinnamate 4-hydrolas in leaves of vitaceae. Planta. 1981; 151:48–52. 10.1007/BF00384236 24301669
3 Hasan M, Bae H. An overview of stress-induced resveratrol synthesis in grapes: Perspectives for resveratrol-enriched grape products. Molecules. 2017; 22(2):294. 10.3390/molecules22020294 28216605
4 Trela BC, Waterhouse AL. Resveratrol: Isomeric molar absorptivities and stability. J Agric Food Chem. 1996; 44(5):1253–1257. 10.1021/jf9504576
5 Flieger J, Tatarczak-Michalewska M, Blicharska E. Characterization of the cis/trans isomerization of resveratrol by high-performance liquid chromatography. Anal Lett. 2017; 50(2):294–303. 10.1080/00032719.2016.1178756
6 Herbig ME, Evers DH. Correlation of hydrotropic solubilization by urea with logD of drug molecules and utilization of this effect for topical formulations. Eur J Pharm Biopharm. 2013; 85(1):158–160. 10.1016/j.ejpb.2013.06.022 23958327
7 Amri A, Chaumeil JC, Sfar S, Charrueau C. Administration of resveratrol: What formulation solutions to bioavailability limitations? J Control Release. 2012; 158(2):182–193. 10.1016/j.jconrel.2011.09.083 21978644
8 O’Neil M. Resveratrol. In: O’Neil M, editor. The Merck Index- An Encyclopedia of Chemicals, Drugs, and Biologicals. Cambridge, UK: Royal Society of Chemistry; 2013. p. 1515.
9 Hanawa F, Tahara S, Mizutani J. Antifungal stress compounds from Veratrum grandiflorum leaves treated with cupric chloride. Phytochemistry. 1992; 31(9):3005–3007. 10.1016/0031-9422(92)83436-3
10 Frémont L. Biological effects of resveratrol. Life Sci. 2000; 66(8):663–673. 10.1016/S0024-3205(99)00410-5 10680575
11 Burns J, Yokota T, Ashihara H, Lean ME, Crozier A. Plant foods and herbal sources of resveratrol. J Agric Food Chem. 2002; 50(11):3337–3340. 10.1021/jf0112973 12010007
12 Lyons MM, Yu C, Toma RB, Cho SY, Reiboldt W, Lee J, van Breemen RB. Resveratrol in raw and baked blueberries and bilberries. J Agric Food Chem. 2003; 51(20):5867–5870. 10.1021/jf034150f 13129286
13 Shrikanta A, Kumar A, Govindaswamy V. Resveratrol content and antioxidant properties of underutilized fruits. J Food Sci Technol. 2015; 52(1):383–390. 10.1007/s13197-013-0993-z 25593373
14 Soleas GJ, Diamandis EP, Goldberg DM. Resveratrol: A molecule whose time has come? And gone? Clin Biochem. 1997; 30(2):91–113. 10.1016/S0009-9120(96)00155-5 9127691
15 Lamuela-Raventos RM, Waterhouse AL. Occurrence of resveratrol in selected California wines by a new HPLC method. J Agric Food Chem. 1993; 41(4):521–523. 10.1021/jf00028a001
16 McMurtrey K. Resveratrol in wine. In: Watkins TR, editor. Wine: Nutritional and Therapeutic Benefits. Washington, D.C.: American Chemical Society; 1997. p. 44–55. 10.1021/bk-1997-0661.ch005
17 Romero-Pérez AI, Lamuela-Raventós RM, Waterhouse AL, de la Torre-Boronat MC. Levels of cis- and trans-resveratrol and their glucosides in white and rosé Vitis vinifera wines from Spain. J Agric Food Chem. 1996; 44(8):2124–2128. 10.1021/jf9507654
18 Adrian M, Jeandet P, Bessis R, Joubert JM. Induction of phytoalexin (resveratrol) synthesis in grapevine leaves treated with aluminum chloride (AlCl3). J Agric Food Chem. 1996; 44(8):1979–1981. 10.1021/jf950807o
19 Jeandet P, Bessis R, Adrian M, Yvin J, Joubert JM. inventors. Use of aluminum chloride as a resveratrol synthesis elicitor. United States patent 06080701; 2000
20 Cantos E, Garcia Viguera C, De Pascual Teresa S, Tomas Berberan FA. Effect of postharvest ultraviolet irradiation on resveratrol and other phenolics of cv. Napolean table grapes. J Agric Food Chem. 2000; 48(10):4606–4612. 10.1021/jf0002948 11052707
21 Calderón AA, Zapata JM, Muñoz R, Pedreño MA, Ros Barceló A. Resveratrol production as a part of the hypersensitive-like response of grapevine cells to an elicitor from Trichoderma viride. New Phytol. 1993; 124(3):455–463. 10.1111/j.1469-8137.1993.tb03836.x
22 Stark-Lorenzen P, Nelke B, Hänßler G, Mühlbach HP, Thomzik JE. Transfer of a grapevine stilbene synthase gene to rice (Oryza sativa L.). Plant Cell Rep. 1997; 16(10):668–673. 10.1007/s002990050299 30727616
23 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) (CAS No. 1746-01-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2006. Technical Report No. 521. https://ntp.niehs.nih.gov/publications/reports/tr/500s/tr521/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr521abs
24 Hipskind JD, Paiva NL. Constitutive accumulation of a resveratrol-glucoside in transgenic alfalfa increases resistance to Phoma medicaginis. Mol Plant Microbe Interact. 2000; 13(5):551–562. 10.1094/MPMI.2000.13.5.551 10796021
25 Morelli R, Das S, Bertelli A, Bollini R, Lo Scalzo R, Das DK, Falchi M. The introduction of the stilbene synthase gene enhances the natural antiradical activity of Lycopersicon esculentum mill. Mol Cell Biochem. 2006; 282(1-2):65–73. 10.1007/s11010-006-1260-7 16317513
26 Edwards JA, Beck M, Riegger C, Bausch J. Safety of resveratrol with examples for high purity, trans-resveratrol, resVida®. Ann N Y Acad Sci. 2011; 1215(1):131–137. 10.1111/j.1749-6632.2010.05855.x 21261651
27 Biasutto L, Mattarei A, Azzolini M, La Spina M, Sassi N, Romio M, Paradisi C, Zoratti M. Resveratrol derivatives as a pharmacological tool. Ann N Y Acad Sci. 2017; 1403(1):27–37. 10.1111/nyas.13401 28675763
28 Hendler SS, Rorvik D. Resveratrol. In: Hendler SS, Rorvik D, editors. PDR for Nutritional Supplements. Montvale, NJ: Medical Economics/Thomson Healthcare; 2001. p. 397–401.
29 Ramírez-Garza SL, Laveriano-Santos EP, Marhuenda-Muñoz M, Storniolo CE, Tresserra-Rimbau A, Vallverdú-Queralt A, Lamuela-Raventós RM. Health effects of resveratrol: Results from human intervention trials. Nutrients. 2018; 10(12):1892. 10.3390/nu10121892 30513922
30 Szkudelski T, Szkudelska K. Resveratrol and diabetes: From animal to human studies. Biochim Biophys Acta. 2015; 1852(6):1145–1154. 10.1016/j.bbadis.2014.10.013 25445538
31 Bonnefont-Rousselot D. Resveratrol and cardiovascular diseases. Nutrients. 2016; 8(5):250. 10.3390/nu8050250 27144581
32 Wahab A, Gao K, Jia C, Zhang F, Tian G, Murtaza G, Chen J. Significance of resveratrol in clinical management of chronic diseases. Molecules. 2017; 22(8):1329. 10.3390/molecules22081329 28820474
33 Baur JA, Sinclair DA. Therapeutic potential of resveratrol: The in vivo evidence. Nat Rev Drug Discov. 2006; 5(6):493–506. 10.1038/nrd2060 16732220
34 Oliveira ALB, Monteiro VVS, Navegantes-Lima KC, Reis JF, Gomes RS, Rodrigues DVS, Gaspar SLF, Monteiro MC. Resveratrol role in autoimmune disease-A mini-review. Nutrients. 2017; 9(12). 10.3390/nu9121306 29194364
35 Malaguarnera L. Influence of resveratrol on the immune response. Nutrients. 2019; 11(5). 10.3390/nu11050946 31035454
36 Sinha D, Sarkar N, Biswas J, Bishayee A. Resveratrol for breast cancer prevention and therapy: Preclinical evidence and molecular mechanisms. Semin Cancer Biol. 2016; 40-41:209–232. 10.1016/j.semcancer.2015.11.001 26774195
37 Camins A, Junyent F, Verdaguer E, Beas-Zarate C, Rojas-Mayorquín AE, Ortuño-Sahagún D, Pallàs M. Resveratrol: An antiaging drug with potential therapeutic applications in treating diseases. Pharmaceuticals (Basel). 2009; 2(3):194–205. 10.3390/ph2030194 27713233
38 Sales JM, Resurreccion AV. Resveratrol in peanuts. Crit Rev Food Sci Nutr. 2014; 54(6):734–770. 10.1080/10408398.2011.606928 24345046
39 Farneti B, Masuero D, Costa F, Magnago P, Malnoy M, Costa G, Vrhovsek U, Mattivi F. Is there room for improving the nutraceutical composition of apple? J Agric Food Chem. 2015; 63(10):2750–2759. 10.1021/acs.jafc.5b00291 25723891
40 Wine Institute. US wine consumption. 2018. https://wineinstitute.org/our-industry/statistics/us-wine-consumption
41 Stervbo U, Vang O, Bonnesen C. A review of the content of the putative chemopreventative phytoalexin resveratrol in red wine. Food Chem. 2007; 101(2):449–457. 10.1016/j.foodchem.2006.01.047
42 McMurtrey KD, Minn J, Pobanz K, Schultz TP. Analysis of wines for resveratrol using direct injection high-pressure liquid chromatography with electrochemical detection. J Agric Food Chem. 1994; 42(10):2077–2080. 10.1021/jf00046a001
43 Sobolev VS, Cole RJ. Trans-resveratrol content in commercial peanuts and peanut products. J Agric Food Chem. 1999; 47(4):1435–1439. 10.1021/jf9809885 10563995
44 The Peanut Institute. History of peanuts, consumption, and affordability. https://peanut-institute.com/peanut-facts/history-of-peanuts-consumption-affordability/
45 Zamora-Ros R, Andres-Lacueva C, Lamuela-Raventos RM, Berenguer T, Jakszyn P, Martinez C, Sanchez MJ, Navarro C, Chirlaque MD, Tormo MJ, et al. Concentrations of resveratrol and derivatives in foods and estimation of dietary intake in a Spanish population: European Prospective Investigation into Cancer and Nutrition (EPIC)-Spain cohort. Br J Nutr. 2008; 100(1):188–196. 10.1017/S0007114507882997 18096094
46 Lu Y, Zamora-Ros R, Chan S, Cross AJ, Ward H, Jakszyn P, Luben R, Opstelten JL, Oldenburg B, Hallmans G, et al. Dietary polyphenols in the aetiology of Crohn’s disease and ulcerative colitis-A multicenter European Prospective Cohort Study (EPIC). Inflamm Bowel Dis. 2017; 23(12):2072–2082. 10.1097/MIB.0000000000001108 28837515
47 Levi F, Pasche C, Lucchini F, Ghidoni R, Ferraroni M, La Vecchia C. Resveratrol and breast cancer risk. Eur J Cancer Prev. 2005; 14(2):139–142. 10.1097/00008469-200504000-00009 15785317
48 Siedlinski M, Boer JM, Smit HA, Postma DS, Boezen HM. Dietary factors and lung function in the general population: Wine and resveratrol intake. Eur Respir J. 2012; 39(2):385–391. 10.1183/09031936.00184110 21852339
49 Patel KR, Scott E, Brown VA, Gescher AJ, Steward WP, Brown K. Clinical trials of resveratrol. Ann N Y Acad Sci. 2011; 1215:161–169. 10.1111/j.1749-6632.2010.05853.x 21261655
50 Web MD. Resveratrol supplements. https://www.webmd.com/heart-disease/resveratrol-supplements
51 Axe J. Resveratrol: The anti-aging powerhouse that’s good for the heart, brain and waistline. 2017. https://draxe.com/all-about-resveratrol/
52 Ratz-Łyko A, Arct J. Resveratrol as an active ingredient for cosmetic and dermatological applications: A review. J Cosmet Laser Ther. 2019; 21(2):84–90. 10.1080/14764172.2018.1469767 29737899
53 Ndiaye M, Philippe C, Mukhtar H, Ahmad N. The grape antioxidant resveratrol for skin disorders: Promise, prospects, and challenges. Arch Biochem Biophys. 2011; 508(2):164–170. 10.1016/j.abb.2010.12.030 21215251
54 Code of Federal Regulations (CFR). 21(Section 190.6).
55 Cottart CH, Nivet-Antoine V, Laguillier-Morizot C, Beaudeux JL. Resveratrol bioavailability and toxicity in humans. Mol Nutr Food Res. 2010; 54(1):7–16. 10.1002/mnfr.200900437 20013887
56 Gambini J, Ingles M, Olaso G, Lopez-Grueso R, Bonet-Costa V, Gimeno-Mallench L, Mas-Bargues C, Abdelaziz KM, Gomez-Cabrera MC, Vina J, et al. Properties of resveratrol: In vitro and in vivo studies about metabolism, bioavailability, and biological effects in animal models and humans. Oxid Med Cell Longev. 2015; 2015:837042. 10.1155/2015/837042 26221416
57 Kapetanovic IM, Muzzio M, Huang Z, Thompson TN, McCormick DL. Pharmacokinetics, oral bioavailability, and metabolic profile of resveratrol and its dimethylether analog, pterostilbene, in rats. Cancer Chemother Pharmacol. 2011; 68(3):593–601. 10.1007/s00280-010-1525-4 21116625
58 Marier JF, Vachon P, Gritsas A, Zhang J, Moreau JP, Ducharme MP. Metabolism and disposition of resveratrol in rats: Extent of absorption, glucuronidation, and enterohepatic recirculation evidenced by a linked-rat model. J Pharmacol Exp Ther. 2002; 302(1):369–373. 10.1124/jpet.102.033340 12065739
59 Mutlu E, Gibbs ST, South N, Pierfelice J, Burback B, Germolec D, Waidyanatha S. Comparative toxicokinetics of Trans-resveratrol and its major metabolites in Harlan Sprague Dawley rats and B6C3F1/N mice following oral and intravenous administration. Toxicol Appl Pharmacol. 2020; 394:114962. 10.1016/j.taap.2020.114962 32205187
60 Bertelli AA, Giovannini L, Stradi R, Bertelli A, Tillement JP. Plasma, urine and tissue levels of trans- and cis-resveratrol (3,4′,5-trihydroxystilbene) after short-term or prolonged administration of red wine to rats. Int J Tissue React. 1996; 18(2-3):67–71. 9063768
61 Roberts VH, Pound LD, Thorn SR, Gillingham MB, Thornburg KL, Friedman JE, Frias AE, Grove KL. Beneficial and cautionary outcomes of resveratrol supplementation in pregnant nonhuman primates. FASEB J. 2014; 28(6):2466–2477. 10.1096/fj.13-245472 24563374
62 Bourque SL, Dolinsky VW, Dyck JRB, Davidge ST. Maternal resveratrol treatment during pregnancy improves adverse fetal outcomes in a rat model of severe hypoxia. Placenta. 2012; 33(5):449–452. 10.1016/j.placenta.2012.01.012 22321195
63 Menet MC, Baron S, Taghi M, Diestra R, Dargere D, Laprevote O, Nivet-Antoine V, Beaudeux JL, Bedarida T, Cottart CH. Distribution of trans-resveratrol and its metabolites after acute or sustained administration in mouse heart, brain, and liver. Mol Nutr Food Res. 2017; 61(8). 10.1002/mnfr.201600686 28160405
64 Böhmdorfer M, Szakmary A, Schiestl RH, Vaquero J, Riha J, Brenner S, Thalhammer T, Szekeres T, Jäger W. Involvement of UDP-glucuronosyltransferases and sulfotransferases in the excretion and tissue distribution of resveratrol in mice. Nutrients. 2017; 9(12):1347. 10.3390/nu9121347 29231856
65 Alberdi G, Rodriguez VM, Miranda J, Macarulla MT, Arias N, Andres-Lacueva C, Portillo MP. Changes in white adipose tissue metabolism induced by resveratrol in rats. Nutr Metab (Lond). 2011; 8(1):29. 10.1186/1743-7075-8-29 21569266
66 Andres-Lacueva C, Macarulla MT, Rotches-Ribalta M, Boto-Ordonez M, Urpi-Sarda M, Rodriguez VM, Portillo MP. Distribution of resveratrol metabolites in liver, adipose tissue, and skeletal muscle in rats fed different doses of this polyphenol. J Agric Food Chem. 2012; 60(19):4833–4840. 10.1021/jf3001108 22533982
67 Detampel P, Beck M, Krähenbühl S, Huwyler J. Drug interaction potential of resveratrol. Drug Metab Rev. 2012; 44(3):253–265. 10.3109/03602532.2012.700715 22788578
68 Vitrac X, Desmouliere A, Brouillaud B, Krisa S, Deffieux G, Barthe N, Rosenbaum J, Merillon JM. Distribution of [14C]-trans-resveratrol, a cancer chemopreventive polyphenol, in mouse tissues after oral administration. Life Sci. 2003; 72(20):2219–2233. 10.1016/S0024-3205(03)00096-1 12628442
69 El-Mohsen MA, Bayele H, Kuhnle G, Gibson G, Debnam E, Kaila Srai S, Rice-Evans C, Spencer JP. Distribution of [3H]trans-resveratrol in rat tissues following oral administration. Br J Nutr. 2006; 96(1):62–70. 10.1079/BJN20061810 16869992
70 Murakami I, Chaleckis R, Pluskal T, Ito K, Hori K, Ebe M, Yanagida M, Kondoh H. Metabolism of skin-absorbed resveratrol into its glucuronized form in mouse skin. PLoS One. 2014; 9(12):e115359. 10.1371/journal.pone.0115359 25506824
71 Maier-Salamon A, Bohmdorfer M, Riha J, Thalhammer T, Szekeres T, Jaeger W. Interplay between metabolism and transport of resveratrol. Ann N Y Acad Sci. 2013; 1290:98–106. 10.1111/nyas.12198 23855471
72 Muzzio M, Huang Z, Hu SC, Johnson WD, McCormick DL, Kapetanovic IM. Determination of resveratrol and its sulfate and glucuronide metabolites in plasma by LC-MS/MS and their pharmacokinetics in dogs. J Pharm Biomed Anal. 2012; 59:201–208. 10.1016/j.jpba.2011.10.023 22079044
73 Walle T, Hsieh F, DeLegge MH, Oatis JE Jr, Walle UK. High absorption but very low bioavailability of oral resveratrol in humans. Drug Metab Dispos. 2004; 32(12):1377–1382. 10.1124/dmd.104.000885 15333514
74 Boocock DJ, Faust GE, Patel KR, Schinas AM, Brown VA, Ducharme MP, Booth TD, Crowell JA, Perloff M, Gescher AJ, et al. Phase I dose escalation pharmacokinetic study in healthy volunteers of resveratrol, a potential cancer chemopreventive agent. Cancer Epidemiol Biomarkers Prev. 2007; 16(6):1246–1252. 10.1158/1055-9965.EPI-07-0022 17548692
75 Brown VA, Patel KR, Viskaduraki M, Crowell JA, Perloff M, Booth TD, Vasilinin G, Sen A, Schinas AM, Piccirilli G, et al. Repeat dose study of the cancer chemopreventive agent resveratrol in healthy volunteers: Safety, pharmacokinetics, and effect on the insulin-like growth factor axis. Cancer Res. 2010; 70(22):9003–9011. 10.1158/0008-5472.CAN-10-2364 20935227
76 Nunes T, Almeida L, Rocha JF, Falcao A, Fernandes-Lopes C, Loureiro AI, Wright L, Vaz-da-Silva M, Soares-da-Silva P. Pharmacokinetics of trans-resveratrol following repeated administration in healthy elderly and young subjects. J Clin Pharmacol. 2009; 49(12):1477–1482. 10.1177/0091270009339191 19797536
77 Bode LM, Bunzel D, Huch M, Cho GS, Ruhland D, Bunzel M, Bub A, Franz CM, Kulling SE. In vivo and in vitro metabolism of trans-resveratrol by human gut microbiota. Am J Clin Nutr. 2013; 97(2):295–309. 10.3945/ajcn.112.049379 23283496
78 Goldberg DM, Yan J, Soleas GJ. Absorption of three wine-related polyphenols in three different matrices by healthy subjects. Clin Biochem. 2003; 36(1):79–87. 10.1016/S0009-9120(02)00397-1 12554065
79 Meng X, Maliakal P, Lu H, Lee MJ, Yang CS. Urinary and plasma levels of resveratrol and quercetin in humans, mice, and rats after ingestion of pure compounds and grape juice. J Agric Food Chem. 2004; 52(4):935–942. 10.1021/jf030582e 14969553
80 la Porte C, Voduc N, Zhang G, Seguin I, Tardiff D, Singhal N, Cameron DW. Steady-state pharmacokinetics and tolerability of trans-resveratrol 2000 mg twice daily with food, quercetin and alcohol (ethanol) in healthy human subjects. Clin Pharmacokinet. 2010; 49(7):449–454. 10.2165/11531820-000000000-00000 20528005
81 Vitaglione P, Sforza S, Galaverna G, Ghidini C, Caporaso N, Vescovi PP, Fogliano V, Marchelli R. Bioavailability of trans-resveratrol from red wine in humans. Mol Nutr Food Res. 2005; 49(5):495–504. 10.1002/mnfr.200500002 15830336
82 Aumont V, Krisa S, Battaglia E, Netter P, Richard T, Merillon JM, Magdalou J, Sabolovic N. Regioselective and stereospecific glucuronidation of trans- and cis-resveratrol in human. Arch Biochem Biophys. 2001; 393(2):281–289. 10.1006/abbi.2001.2496 11556815
83 Patel KR, Brown VA, Jones DJ, Britton RG, Hemingway D, Miller AS, West KP, Booth TD, Perloff M, Crowell JA, et al. Clinical pharmacology of resveratrol and its metabolites in colorectal cancer patients. Cancer Res. 2010; 70(19):7392–7399. 10.1158/0008-5472.CAN-10-2027 20841478
84 Howells LM, Berry DP, Elliott PJ, Jacobson EW, Hoffmann E, Hegarty B, Brown K, Steward WP, Gescher AJ. Phase I randomized, double-blind pilot study of micronized resveratrol (SRT501) in patients with hepatic metastases—safety, pharmacokinetics, and pharmacodynamics. Cancer Prev Res (Phila). 2011; 4(9):1419–1425. 10.1158/1940-6207.CAPR-11-0148 21680702
85 Williams LD, Burdock GA, Edwards JA, Beck M, Bausch J. Safety studies conducted on high-purity trans-resveratrol in experimental animals. Food Chem Toxicol. 2009; 47(9):2170–2182. 10.1016/j.fct.2009.06.002 19505523
86 Crowell JA, Korytko PJ, Morrissey RL, Booth TD, Levine BS. Resveratrol-associated renal toxicity. Toxicol Sci. 2004; 82(2):614–619. 10.1093/toxsci/kfh263 15329443
87 Elliott PJ, Walpole S, Morelli L, Lambert PD, Lunsmann W, Westphal CH, Lavu S. Resveratrol/SRT-501. Drugs Future. 2009; 34(4):291. 10.1358/dof.2009.034.04.1360696
88 Johnson WD, Morrissey RL, Usborne AL, Kapetanovic I, Crowell JA, Muzzio M, McCormick DL. Subchronic oral toxicity and cardiovascular safety pharmacology studies of resveratrol, a naturally occurring polyphenol with cancer preventive activity. Food Chem Toxicol. 2011; 49(12):3319–3327. 10.1016/j.fct.2011.08.023 21939727
89 Horn TL, Cwik MJ, Morrissey RL, Kapetanovic I, Crowell JA, Booth TD, McCormick DL. Oncogenicity evaluation of resveratrol in p53(+/-) (p53 knockout) mice. Food Chem Toxicol. 2007; 45(1):55–63. 10.1016/j.fct.2006.07.015 16965847
90 Chow HHS, Garland LL, Hsu C-H, Vining DR, Chew WM, Miller JA, Perloff M, Crowell JA, Alberts DS. Resveratrol modulates drug- and carcinogen-metabolizing enzymes in a healthy volunteer study. Cancer Prev Res (Phila). 2010; 3(9):1168–1175. 10.1158/1940-6207.CAPR-09-0155 20716633
91 Cottart CH, Nivet-Antoine V, Beaudeux JL. Review of recent data on the metabolism, biological effects, and toxicity of resveratrol in humans. Mol Nutr Food Res. 2014; 58(1):7–21. 10.1002/mnfr.201200589 23740855
92 Brâkenhielm E, Cao R, Cao Y. Suppression of angiogenesis, tumor growth, and wound healing by resveratrol, a natural compound in red wine and grapes. FASEB J. 2001; 15(10):1798–1800. 10.1096/fj.01-0028fje 11481234
93 Kyselova V, Peknicova J, Buckiova D, Boubelik M. Effects of p-nonylphenol and resveratrol on body and organ weight and in vivo fertility of outbred CD-1 mice. Reprod Biol Endocrinol. 2003; 1:30. 10.1186/1477-7827-1-30 12749770
94 Kim IQ, Marikawa Y. Embryoid body test with morphological and molecular endpoints implicates potential developmental toxicity of trans-resveratrol. Toxicol Appl Pharmacol. 2018; 355:211–225. 10.1016/j.taap.2018.07.006 29990529
95 Juan ME, Gonzalez-Pons E, Munuera T, Ballester J, Rodriguez-Gil JE, Planas JM. trans-Resveratrol, a natural antioxidant from grapes, increases sperm output in healthy rats. J Nutr. 2005; 135(4):757–760. 10.1093/jn/135.4.757 15795430
96 Bowers JL, Tyulmenkov VV, Jernigan SC, Klinge CM. Resveratrol acts as a mixed agonist/antagonist for estrogen receptors alpha and beta. Endocrinology. 2000; 141(10):3657–3667. 10.1210/endo.141.10.7721 11014220
97 Gehm BD, McAndrews JM, Chien PY, Jameson JL. Resveratrol, a polyphenolic compound found in grapes and wine, is an agonist for the estrogen receptor. Proc Natl Acad Sci USA. 1997; 94(25):14138–14143. 10.1073/pnas.94.25.14138 9391166
98 Banu SK, Stanley JA, Sivakumar KK, Arosh JA, Burghardt RC. Resveratrol protects the ovary against chromium-toxicity by enhancing endogenous antioxidant enzymes and inhibiting metabolic clearance of estradiol. Toxicol Appl Pharmacol. 2016; 303:65–78. 10.1016/j.taap.2016.04.016 27129868
99 Atli M, Engin-Ustun Y, Tokmak A, Caydere M, Hucumenoglu S, Topcuoglu C. Dose dependent effect of resveratrol in preventing cisplatin-induced ovarian damage in rats: An experimental study. Reprod Biol. 2017; 17(3):274–280. 10.1016/j.repbio.2017.07.001 28716446
100 Alamo A, Condorelli RA, Mongioi LM, Cannarella R, Giacone F, Calabrese V, La Vignera S, Calogero AE. Environment and male fertility: Effects of benzo-alpha-pyrene and resveratrol on human sperm function in vitro. J Clin Med. 2019; 8(4). 10.3390/jcm8040561 31027257
101 Ourique GM, Pes TS, Saccol EM, Finamor IA, Glanzner WG, Baldisserotto B, Pavanato MA, Goncalves PB, Barreto KP. Resveratrol prevents oxidative damage and loss of sperm motility induced by long-term treatment with valproic acid in Wistar rats. Exp Toxicol Pathol. 2016; 68(8):435–443. 10.1016/j.etp.2016.07.001 27432062
102 Singh I, Goyal Y, Ranawat P. Potential chemoprotective role of resveratrol against cisplatin induced testicular damage in mice. Chem Biol Interact. 2017; 273:200–211. 10.1016/j.cbi.2017.05.024 28606469
103 Ortega I, Duleba AJ. Ovarian actions of resveratrol. Ann N Y Acad Sci. 2015; 1348(1):86–96. 10.1111/nyas.12875 26315293
104 Liu MJ, Sun AG, Zhao SG, Liu H, Ma SY, Li M, Huai YX, Zhao H, Liu HB. Resveratrol improves in vitro maturation of oocytes in aged mice and humans. Fertil Steril. 2018; 109(5):900–907. 10.1016/j.fertnstert.2018.01.020 29778389
105 Wong DH, Villanueva JA, Cress AB, Duleba AJ. Effects of resveratrol on proliferation and apoptosis in rat ovarian theca-interstitial cells. Mol Hum Reprod. 2010; 16(4):251–259. 10.1093/molehr/gaq002 20067985
106 Banaszewska B, Wrotynska-Barczynska J, Spaczynski RZ, Pawelczyk L, Duleba AJ. Effects of resveratrol on polycystic ovary syndrome: A double-blind, randomized, placebo-controlled trial. J Clin Endocrinol Metab. 2016; 101(11):4322–4328. 10.1210/jc.2016-1858 27754722
107 Huang MC, White KL, Elmore SA, Guo TL, Germolec D. Immunotoxicity studies of trans-resveratrol in male B6C3F1/N mice. J Immunotoxicol. 2020; 17(1):194–201. 10.1080/1547691X.2020.1833113 33213203
108 Espinoza JL, Trung LQ, Inaoka PT, Yamada K, An DT, Mizuno S, Nakao S, Takami A. The repeated administration of resveratrol has measurable effects on circulating T-cell subsets in humans. Oxid Med Cell Longev. 2017; 2017:6781872. 10.1155/2017/6781872 28546852
109 Moussa C, Hebron M, Huang X, Ahn J, Rissman RA, Aisen PS, Turner RS. Resveratrol regulates neuro-inflammation and induces adaptive immunity in Alzheimer’s disease. J Neuroinflammation. 2017; 14(1):1. 10.1186/s12974-016-0779-0 28086917
110 Di Renzo L, Marsella LT, Carraro A, Valente R, Gualtieri P, Gratteri S, Tomasi D, Gaiotti F, De Lorenzo A. Changes in LDL oxidative status and oxidative and inflammatory gene expression after red wine intake in healthy people: A randomized trial. Mediators Inflamm. 2015; 2015:317348. 10.1155/2015/317348 26101461
111 Matsuoka A, Furuta A, Ozaki M, Fukuhara K, Miyata N. Resveratrol, a naturally occurring polyphenol, induces sister chromatid exchanges in a Chinese hamster lung (CHL) cell line. Mutat Res. 2001; 494(1-2):107–113. 10.1016/S1383-5718(01)00184-X 11423350
112 Schmitt E, Lehmann L, Metzler M, Stopper H. Hormonal and genotoxic activity of resveratrol. Toxicol Lett. 2002; 136(2):133–142. 10.1016/S0378-4274(02)00290-4 12425963
113 Guo X, Ni J, Dai X, Zhou T, Yang G, Xue J, Wang X. Biphasic regulation of spindle assembly checkpoint by low and high concentrations of resveratrol leads to the opposite effect on chromosomal instability. Mutat Res Genet Toxicol Environ Mutagen. 2018; 825:19–30. 10.1016/j.mrgentox.2017.11.004 29307372
114 Matsuoka A, Takeshita K, Furuta A, Ozaki M, Fukuhara K, Miyata N. The 4′-hydroxy group is responsible for the in vitro cytogenetic activity of resveratrol. Mutat Res. 2002; 521(1-2):29–35. 10.1016/S1383-5718(02)00211-5 12438001
115 Liu Y, Wu X, Hu X, Chen Z, Liu H, Takeda S, Qing Y. Multiple repair pathways mediate cellular tolerance to resveratrol-induced DNA damage. Toxicol In Vitro. 2017; 42:130–138. 10.1016/j.tiv.2017.04.017 28431926
116 Fukuhara K, Miyata N. Resveratrol as a new type of DNA-cleaving agent. Bioorg Med Chem Lett. 1998; 8(22):3187–3192. 10.1016/S0960-894X(98)00585-X 9873700
117 Abraham SK, Khandelwal N, Hintzsche H, Stopper H. Antigenotoxic effects of resveratrol: Assessment of in vitro and in vivo response. Mutagenesis. 2016; 31(1):27–33. 26152226
118 King-Herbert A, Thayer K. NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. 10.1080/01926230600935938 17162538
119 King-Herbert AP, Sills RC, Bucher JR. Commentary: Update on animal models for NTP studies. Toxicol Pathol. 2010; 38(1):180–181. 10.1177/0192623309356450 20019353
120 Hedrich HJ. Taxonomy and stocks and strains. In: Suckow M, Weisbroth S, Franklin C, editors. The Laboratory Rat. Burlington, MA: Elsevier Academic; 2006. p. 71–92. 10.1016/B978-012074903-4/50006-6
121 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
122 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
123 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
124 Armitage P. Statistical Methods in Medical Research. Oxford: Blackwell; 1971.
125 Rao JN, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
126 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
127 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
128 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
129 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
130 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
131 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-doe control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
132 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
133 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2): 133–145. 10.1093/biomet/41.1-2.133
134 Davison AC, Hinkley DV. Bootstrap methods and their application. Cambridge, UK: Cambridge University Press; 1997. 10.1017/CBO9780511802843
135 Datta S, Satten GA. Rank-sum tests for clustered data. J Am Stat Assoc. 2005; 100(471):908–915. 10.1198/016214504000001583
136 Dixon W, Massey F. Introduction to statistical analysis. New York, NY: McGraw Hill Book Company Inc; 1957. 10.2307/2332898
137 Kalbfleisch JD, Lawless JF. The analysis of panel data under a Markov assumption. J Am Stat Assoc. 1985; 80(392):863–871. 10.1080/01621459.1985.10478195
138 Code of Federal Regulations (CFR). 21(Part 58).
139 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
140 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67:233–241. 7021938
141 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
142 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
143 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
144 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden H. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 Suppl 18:1–14. 10.1002/em.2850160502 2091921
145 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
146 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
147 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
148 Shelby MD, Witt KL. Comparison results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995;25:302–313. 10.1002/em.2850250407 7607185
149 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
150 National Toxicology Program (NTP). TOX-102: Toxicity report tables & curves pathology tables, survival and growth curves from NTP short-term and genetic toxicology studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2020. 10.22427/NTP-DATA-TOX-102
151 Reagan-Shaw S, Nihal M, Ahmad N. Dose translation from animal to human studies revisited. FASEB J. 2008; 22(3):659–661. 10.1096/fj.07-9574LSF 17942826
152 Care AS, Sung MM, Panahi S, Gragasin FS, Dyck JRB, Davidge ST, Bourque SL. Perinatal resveratrol supplementation to spontaneously hypertensive rat dams mitigates the development of hypertension in adult offspring. Hypertension. 2016; 67(5):1038–1044. 10.1161/HYPERTENSIONAHA.115.06793 26928803
153 Chao W, Xuexin Z, Jun S, Ming C, Hua J, Li G, Tan C, Xu W. Effects of resveratrol on cell growth and prolactin synthesis in GH3 cells. Exp Ther Med. 2014; 7(4):923–928. 10.3892/etm.2014.1544 24669252
154 Moscovitz JE, Aleksunes LM. Establishment of metabolism and transport pathways in the rodent and human fetal liver. Int J Mol Sci. 2013; 14(12):23801–23827. 10.3390/ijms141223801 24322441
155 National Toxicology Program (NTP). NTP nonneoplastic lesion atlas- Renal, kidney. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program. https://ntp.niehs.nih.gov/nnl/urinary/kidney/necp/index.htm
156 Nolte T, Brander-Weber P, Dangler C, Deschl U, Elwell MR, Greaves P, Hailey R, Leach MW, Pandiri AR, Rogers A, et al. Nonproliferative and proliferative lesions of the gastrointestinal tract, pancreas and salivary glands of the rat and mouse. J Toxicol Pathol. 2016; 29(1 Suppl):1S–125S. 10.1293/tox.29.1S 26973378
157 Boyle MC, Crabbs TA, Wyde ME, Painter JT, Hill GD, Malarkey DE, Lieuallen WG, Nyska A. Intestinal lymphangiectasis and lipidosis in rats following subchronic exposure to indole-3-carbinol via oral gavage. Toxicol Pathol. 2012; 40(4):561–576. 10.1177/0192623311436178 22328411
158 Friedman HI, Nylund B. Intestinal fat digestion, absorption, and transport. A review. Am J Clin Nutr. 1980; 33(5):1108–1139. 10.1093/ajcn/33.5.1108 6989228
159 Sells DM, Brix AE, Nyska A, Jokinen MP, Orzech DP, Walker NJ. Respiratory tract lesions in noninhalation studies. Toxicol Pathol. 2007; 35(1):170–177. 10.1080/01926230601059969 17325986
160 Reed CJ. Drug metabolism in the nasal cavity: Relevance to toxicology. Drug Metab Rev. 1993; 25(1-2):173–205. 10.3109/03602539308993975 8449146
161 Henry LA, Witt DM. Resveratrol: Phytoestrogen effects on reproductive physiology and behavior in female rats. Horm Behav. 2002; 41(2):220–228. 10.1006/hbeh.2001.1754 11855907
162 Calabrese EJ, Mattson MP, Calabrese V. Resveratrol commonly displays hormesis: Occurrence and biomedical significance. Hum Exp Toxicol. 2010; 29(12):980–1015. 10.1177/0960327110383625 21115559
163 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
164 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
165 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
166 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117