# Discussion

Trans-resveratrol (RES) has captured the attention of researchers and clinicians for years as a potential treatment or preventive natural product for various conditions, including cancer, cardiometabolic diseases, and neurodegenerative diseases. The development of novel techniques and strategies to improve its bioavailability and bioefficacy suggests continued prevalence and use of RES both therapeutically and in consumer products. Due to its low bioavailability, RES used in dietary supplements and in clinical trials can be found at high concentrations, with doses up to 5 g per day. The National Toxicology Program (NTP) conducted the present studies to address key knowledge gaps in resveratrol safety, especially those for perinatal RES exposure.

The doses used in the present studies approximate human exposure. Oral doses of 2.5 and 5 g RES in humans, as used in some clinical studies,^59^ are similar to an oral gavage dose of 312.5 and 625 mg/kg/day in rats (625 and 1,250 mg/kg/day in mice), after adjusting for body surface area.^151^ For example, 625 mg/kg exposure in rats corresponds to a human equivalent dose (HED) of 101.4 mg/kg, or a single oral dose of 6.1 to 9.1 g, accounting for human body weight ranging from 60 to 90 kg. These HEDs are 1.2- to 1.8-fold higher than the doses used in clinical studies. Furthermore, a toxicokinetic study of RES in the same strains of rodents showed that systemic exposures following a single gavage dose at the same dose levels used in this study were within an order of magnitude of those observed in a clinical study.^59^ Rat-to-human exposure multiples calculated using internal exposure measures, maximum concentration (C_max_), and area under the concentration-time curve (AUC), were 2.2–3.4-fold and 9.4–10.4-fold, respectively.^59^ Thus, the internal doses in the present study in animals are similar to what could be expected with therapeutic use of RES in humans. The 5-day exposure paradigm in these rodent studies likely affected the amount of time animals maintained a steady-state internal dose, given the rapid metabolism of RES, but may not have affected the findings substantially given the length of the study. Overall, however, these internal concentrations are higher than would be expected after moderate RES supplementation or from RES obtained from foods.

Given the potential use of RES in women of child-bearing age, perinatal exposure was included in the current Wistar Han rat study. In this study, there were no significant effects of RES on reproductive parameters. Lower mean body weights and body weight gains of dams in dosed groups ≥156 mg RES/kg body weight/day (mg/kg/day) during late gestation were observed. There were no dose-related effects on total or live litter size, pup survival, or pup weight on postnatal day (PND) 1. These findings corroborate previous studies in rodents that show no significant effects on litter size or reproduction after exposure to RES during gestation.^85,87,93,152^ Throughout lactation, male and female Wistar Han rat pups exposed to RES (≥312.5 mg/kg/day) had lower mean body weights than the vehicle control groups, which potentially could be due to maternal effects and/or postnatal effects on the pups. These animals were exposed to RES in utero and during lactation, both via milk and (starting on PND 12) via direct oral gavage. However, by the end of the 3-month study, RES-dosed Wistar Han rat offspring had similar mean body weights compared to vehicle control animals. A similar growth pattern was observed in a study of spontaneously hypertensive rats given RES in the diet from the beginning of gestation through PND 21 (4 g/kg diet).^152^ Assuming feed consumption of approximately 20 g/animal/day and an average body weight of 300 g during gestation, the maternal exposure would be equivalent to 270 mg/kg/day in that study. Although there was no effect of gestational RES exposure on maternal or fetal body weight, mean body weights of offspring from RES-dosed dams were lower (17%) than vehicle control animals by PND 21; dams continued to consume RES in the diet during lactation.^152^ By 5 weeks of age, there was no difference in body weights among the offspring.^152^ The authors of that study proposed RES may affect offspring growth by altering quantity or quality of milk production via altered prolactin synthesis, as shown in Chao et al.^153^ Taken together, the findings suggested a developmental effect of RES resulting in growth retardation, potentially due to effects on the dam during gestation or lactation.^152^

In the current Wistar Han rat studies, RES and its metabolites were found in dam plasma and in whole fetuses and pups, with no clear sex difference. Internal concentrations of RES in this study were lower than doses commonly used for in vitro studies, such as those that evaluate genetic toxicity. The presence of RES and its metabolites in fetal tissue suggested low maternal transfer, and the presence of RES and its metabolites in PND 4 whole pups suggested lactational transfer. Data regarding maternal RES concentrations during pregnancy or RES in breast milk or amniotic fluid is limited and only include RES concentrations. In a study of Japanese macaques exposed to 0.37% RES via the diet during pregnancy, gestational transfer of RES was reported with slightly higher RES concentrations measured in the plasma of the fetus than the dam.^61^ Another study in rats described placental transfer of RES following exposure to 4 g/kg RES via the diet from gestation day (GD) 7 to GD 21.^62^ RES metabolites were detected in the fetuses and pups in the current study, generally with more trans-resveratrol-3-O-B-D-glucuronide (trans-R3G) than trans-resveratrol-3-sulfate (trans-R3S) and a low percentage of transfer from the dams. Because some sulfotransferases, but very few uridine 5'-diphospho-glucuronosyl transferases, are found in fetal livers,^154^ some metabolism (i.e., sulfonation) might occur in the fetus; however, it is more likely that most of the RES metabolites detected in the fetus have crossed the placenta. Because RES and its metabolites were detected in fetuses and pups, developmental effects of RES could be related to direct effects of RES or metabolite exposure in addition to indirect effects through the dam.

RES exposure has been associated with decreased body weights of similar magnitude in other rat studies. In a 13-week exposure study in adult Wistar rats, mean body weights and body weight gains were approximately 10% lower in the highest exposure group (750 mg/kg/day via the diet) compared to control animals starting at week 4 and throughout the remainder of the study.^85^ In CD^®^ Virus Antibody Free (VAF) rats administered RES via oral gavage for four weeks, terminal mean body weights of male rats were 12% lower than vehicle control animals; however, in females, mean body weights were slightly higher than vehicle control animals (2%) in the high dose group (3,000 mg/kg/day).^86^ Another 90-day oral gavage study in CD (Crl:CD^®^[SD]IGS) rats showed no effect on body weights in males and slight reductions (8%–9%) in females during weeks 10–13 at the 1,000 mg/kg/day dose.^88^ In the current study, B6C3F1/N mice administered RES did not have significant differences in body weight. Similarly, in a multigenerational drinking water study in CD-1 (ICR) mice, male and female RES-exposed mice in the parental generation had 6%–9% lower mean body weights than control animals, which was not significant; there was no appreciable difference in the F_1_ generation.^93^ Decreased body weight is a common endpoint for establishing the no-observed-effect level (NOEL) in other rodent studies of RES. The NOELs in the present study were 156 mg/kg/day in rats and 312 mg/kg/day in mice, which are consistent with findings in other oral administration studies that report NOELs in rats of 200,^88^ 300,^86^ and 750^85^ mg/kg/day.

Dose-related histopathological findings in the current studies consisted of renal and intestinal lesions in Wistar Han rats and nasal lesions in B6C3F1/N mice. The renal lesions in Wistar Han rats consisted of nephropathy and renal tubule dilatation in male and female rats and renal pelvis dilatation in female rats. The nephropathy lesions were of minimal severity and characterized by focal to multifocal small clusters of proximal tubules within the renal cortex that displayed cytoplasmic basophilia (regeneration), thickened basement membranes, and peritubular mononuclear cell infiltrates. This lesion is also known as chronic progressive nephropathy (CPN) and is a spontaneous background lesion in rodents whose incidence/severity may be exacerbated by various chemicals.^155^ The exact etiology of CPN is unknown, but it is influenced by various physiological factors such as caloric intake, dietary protein content, and male hormones. In young adult rats, the early lesion consists of foci of basophilic proximal tubules with crowded nuclei and/or a thickened basement membrane. With age, the lesion progresses and may present prominent hyaline casts in the medullary region, tubule atrophy, tubule dilatation, focal glomerular sclerosis, glomerular atrophy, mononuclear cell infiltration and transitional cell hyperplasia of the renal pelvis lining. Renal tubule dilatation was diagnosed when it occurred in the renal medullary region and was not associated with any histological evidence of nephropathy or lower urinary tract obstruction. Typically, only one or a few tubules were affected, and the dilated tubules frequently contained an eosinophilic intraluminal material, consistent with protein. The renal pelvis dilatation occurred with a positive trend in female Wistar Han rats only and was characterized by distention of the renal pelvis without histological evidence of lower urinary tract obstruction and without renal papilla atrophy. Although there are many etiologies associated with this lesion, most are due to lower urinary tract obstruction. In this study, the cause was undetermined. Some of the same renal lesions were also reported in a 28-day rat study.^86^ Lesions observed included tubule dilatation, papillary necrosis, hyperplasia of the pelvic epithelium, and nephropathy, among others. Most lesions occurred in the male and female 3,000 mg/kg/day dosed groups.^86^

The intestinal lesions in male and female Wistar Han rats consisted of minimal to mild lymphatic ectasia of the lacteals within the jejunum villous tips and the lymphatic vessels in the subepithelial dome region of the Peyer’s patches. This lesion is also known as lymphangiectasis.^156^ The cause of the lymphatic ectasia in these tissues was not determined. The jejunum contains lacteals that are lymphatic capillaries in the villous tips. These function to absorb products from the breakdown of dietary fats (fatty acids and glycerol). The lacteals can merge to form larger lymphatic vessels that transport chyle via the lymphatic system to the thoracic duct where it is emptied into the blood stream. Peyer’s patches are a part of this lymphatic system, presenting as prominent masses of lymphatic tissue located in the submucosa and lamina propria throughout the rodent small intestine. Lymphatics within the Peyer’s patches are involved in the lymphatic drainage of the intestines and function in immune surveillance. A similar histological finding was described in an NTP study of Fischer 344 (F344/N) rats administered indole-3-carbinol via oral gavage.^157^ These animals demonstrated a dose-related dilatation of lymphatics (lymphangiectasis) of the duodenum, jejunum, and mesenteric lymph nodes. Material within dilated lacteals stained with Oil Red O and Sudan black, consistent with lipid accumulation. Electron microscopic evaluation confirmed extracellular lipid accumulation within the villar lamina propria, lacteals, and within villar macrophages. It was suggested that the accumulation of large lipid droplets was possibly due to an impairment of lipid transport in the lacteals. For a more detailed description of lipid transport, see Friedman and Nylund.^158^

The dose-related nasal lesion in female B6C3F1/N mice consisted of respiratory metaplasia of the olfactory epithelium. Respiratory metaplasia in this study was of minimal severity and defined as transformation or replacement of olfactory epithelium with a more resistant, ciliated, columnar epithelium that resembles respiratory epithelium. The presence of this metaplasia implies that loss of olfactory epithelium has occurred through necrosis or atrophy and is considered an adaptive change. The lesions were focally extensive and occurred most often in the dorsal aspect (dorsal medial meatus) of the nasal cavity at Level II. Mechanisms of exposure of nasal tissues to toxicants in noninhalation studies can be via the bloodstream or via regurgitation/reflux, inhalation of volatiles from the stomach, or by exhaling the parent or a toxic metabolite.^159^ Metabolism of a parent compound or metabolites that arrive from the blood stream may occur in respiratory tissues and studies have shown that significant enzymatic activity occurs in the cytoplasm of olfactory epithelium; the resulting metabolism may detoxify a material or result in a more toxic metabolite.^159,160^

RES-dosed male and female mice had higher liver weights than vehicle control animals, with significantly increased relative weights among the ≥625 mg/kg/day female dosed groups and significantly increased absolute and relative weights in the 2,500 mg/kg/day male dosed group. These organ weight changes did not correlate with any microscopic observations. Hepatomegaly was also reported in CD male and female rats given 1,000 mg/kg/day for 13 weeks, along with increases in bilirubin.^88^ In that study, there was no microscopic evidence of hepatotoxicity. The increase in liver weight observed may be due to induction of hepatic enzymes involved in metabolism and/or antioxidant pathways.^33^

Data from Wistar Han rats and B6C3F1/N mice presented here provide little indication of reproductive toxicity in males and females. There were no significant differences in testes weights and no microscopic findings in the male or female reproductive tracts of rats or mice. Differences in cauda epididymis sperm count and alterations in vaginal cytology in B6C3F1/N mice were not considered related to dose as they were small in magnitude and not consistently dose dependent. Similarly, other studies in rodents report no change in reproductive organ weight or histopathology at doses up to 1,000 mg/kg/day^85,88^ or no significant differences in sperm count/quality, ovarian morphology, or estrous cycling at doses up to 750 mg/kg/day.^85,93^ There have been indications, however, of an effect of lower doses of RES on reproductive biology. In Sprague Dawley rats administered 20 mg/kg/day via gavage for 90 days, sperm counts were higher in RES-dosed rats, accompanied by increases in seminiferous tubule density, but without changes in testes weight or sperm quality.^95^ In addition, RES consumption was linked to increased ovary weight and disrupted estrous cycling in Sprague Dawley rats exposed to 100 μM RES in drinking water.^161^ While the differences in findings could be attributed to hormetic effects of RES, evidence for such is limited to in vitro and a few in vivo studies.^162^ Additional studies evaluating the dose response of the reproductive effects would help clarify these disparate findings and the underlying mechanisms.

Under the conditions of this study, the lowest-observed-effect level (LOEL) was 312.5 mg/kg/day in rats as indicated by significantly decreased pup mean body weights of Wistar Han rats exposed perinatally. These body weight differences were resolved in the rat pups by the end of the 3-month study. In B6C3F1/N mice, the LOEL was 625 mg/kg/day as indicated by significantly increased relative liver weights in females; however, these changes in liver weight were not associated with microscopic lesions. The no-observed-effect levels were 156 mg/kg/day in rats and 312 mg/kg/day in mice. Target organs included the kidney and small intestine in rats and the nose in female mice. There was no evidence of genetic toxicity in the micronucleus assay of RES at oral gavage doses up to 1,250 mg/kg/day in Wistar Han rats or up to 2,500 mg/kg/day in B6C3F1/N mice. No clear effects on reproductive parameters were observed. The presence of RES and its metabolites in fetal tissue suggested low maternal transfer, and the presence of RES and its metabolites in PND 4 whole pups suggested lactational transfer.