# Introduction

Figure 1

Trans-resveratrol (CASRN 501-36-0; Chemical Formula: C_14_H_12_O_3_; Molecular Weight: 228.25)

Synonyms: resveratrol; 3,4',5-stilbenetriol; 3,4',5-trihydroxystilbene; 3,5,4'-trihydroxystilbene.

Image generated with ChemSpider^1^

## Chemical and Physical Properties

Trans-resveratrol (RES) is a polyphenolic phytoalexin produced by some plants in response to ultraviolet (UV) light, injury, or infection. Stilbene synthase is the final enzyme in the RES synthesis pathway and is stimulated by UV light or fungal infections.^2,3^ Due to its double bond, resveratrol can exist in the trans- or cis-form; the trans-isomer is more sterically stable.^4^ Conversion between the trans- and cis-forms can occur with exposure to UV light and is dependent on concentration and pH.^5^ RES has low water solubility (<0.05 mg/mL) and is more soluble in organic solvents (log K_ow_ of 3.10).^6,7^ It is an off-white powder with a melting point of 253–255ºC.^8^ UV absorbance of trans- and cis-resveratrol in ethanol is 306–320 nm and 286–288 nm, respectively.^4^

## Production, Use, and Human Exposure

RES can be isolated from the leaves of white hellebore (Veratrum grandiflorum) and roots of Japanese knotweed (Polygonum cuspidatum), plants used in traditional medicine.^9,10^ In addition, RES is found in several foods, including grapes, peanuts, pistachios, itadori tea, and various berries.^11-13^ RES is also present in wine and is found at higher concentrations in red wine.^10,14-17^

RES can be commercially produced by isolating it from grape plants, which can be induced to produce greater quantities by applying aluminum chloride or aluminum sulfate to grape shoots and vines.^18,19^ Production of RES in harvested grapes increased twofold with irradiation by UVB light and threefold with irradiation by UVC light.^20^ RES can also be produced by treating cell suspension cultures of grapes with Onozuka R-10, a cellulase derived from the fungus Trichoderma viride.^21^ In addition, stilbene synthase genes have been isolated and inserted into plants, creating transgenic varieties of tobacco, grape, tomatoes, potatoes, rice, and alfalfa with higher RES concentrations.^22-25^ Lastly, RES can be synthesized from chemical precursors, as is the case with DSM Nutritional Products’ resVida^®^.^26^

Due to its low water solubility, RES bioavailability is low to moderate. Thus, formulations for increasing RES bioavailability have been developed, involving micro- and nanoparticle excipients, liposomes, and complexation with cyclic oligosaccharides.^7^ Research is ongoing to improve the bioavailability and bioefficacy (e.g., increased concentration at tissue-specific sites) of prodrugs for RES.^27^

Traditional Asian medicine has long used RES from the root of P. cuspidatum as a tonic to treat hypertension and cardiovascular disease, among other uses.^10,28,29^ Primarily due to its antioxidant and anti-inflammatory effects observed in laboratory studies, RES has been marketed to treat and prevent a variety of diseases, improve glucose metabolism (e.g., beneficial effects on insulin sensitivity),^30^ provide neuro- and cardio-protection,^31-33^ enhance the immune system,^34,35^ protect against cancer,^36^ and prolong life.^37^

Human exposure to RES is mainly through ingestion, particularly of peanuts, grapes, and related products.^38,39^ In 2018, per capita wine consumption in the United States was 11.2 L or 2.95 gallons.^40^ The content of RES in wine depends on the variety of grape used and on the geographic region in which the grapes were grown. The average red wine contains 1.9 ± 1.7 mg/L RES,^41^ whereas the average white wine contains ≤0.02 mg/L.^42^

RES levels in peanuts and peanut products are lower than those in grape products and are summarized in a review by Sales and Resurreccion.^38^ In one study, RES concentrations were 0.06 μg/g (0.24 nmol/g) for roasted peanuts, 0.32 μg/g (1.42 nmol/g) for peanut butter, and 5.14 μg/g (22.51 nmol/g) for boiled peanuts.^43^ Hendler and Rorvik^28^ reported the levels of RES in peanuts to be 0.02–1.79 μg/g (0.09–7.84 nmol/g). Estimates of U.S. peanut consumption per capita annually from 2012 to 2018 range from 6.5 to 7.5 pounds, with peanut butter the primary product consumed.^44^

Although dietary intake of total polyphenols has been documented in several studies, comprehensive estimations of RES consumption through diet are limited. One study involving the European Prospective Investigation into Cancer and Nutrition (Spain) cohort evaluated dietary intake of RES and its derivative, piceid.^45^ Using a compilation of studies on the amounts of trans- and cis-resveratrol in various foods, researchers estimated RES intake in the Spanish cohort to be 100 μg/day. Intake was highest in older men. The primary sources of RES were wine and grape juice (98.4% and 1.6%, respectively); peanuts, pistachios, and berries contributed <0.01%.^45^ Studies in other European cohorts have estimated RES intake through wine and grapes to be in the range of 0–200 μg/day.^46-48^ Estimates of RES intake via diet vary between populations and countries due to different food availability and food consumption patterns.

Oral exposure to RES also occurs via dietary supplements. For dietary supplements, amounts found in products and dosage recommendations vary. RES supplements can contain from 1 to 500 mg per tablet or capsule. Although the amount individuals in the general population are taking is unclear, up to 5 g per day has been observed to be safe in clinical trials^49^ and is a recommended upper limit reported on health websites.^50,51^ Due to its antioxidant and potential antiaging properties, RES is being formulated for dermal application through which more direct application to the target tissue is possible, potentially resulting in higher bioavailability.^52,53^ Thus, some dermal exposure to RES is possible.

## Regulatory Status

RES available in dietary supplements is regulated under the U.S. Food, Drug, and Cosmetic Act. Manufacturers and distributors must notify the Food and Drug Administration when they plan to market dietary supplements that contain “new dietary ingredients” (Section 413b of the Act, 21 U.S.C. 350b).^54^

## Absorption, Distribution, Metabolism, and Excretion

A number of animal studies and small clinical trials evaluating kinetics and metabolism of RES are available. They have been reviewed elsewhere,^49,55,56^ but overall findings are summarized here. Generally, RES is rapidly absorbed, highly metabolized in the liver and small intestine, and excreted through urine.

### Experimental Animals

The disposition of RES has been studied primarily in rodents; one limited study was conducted in beagle dogs. In both cases, RES was rapidly absorbed following oral administration.

In male CD or Sprague Dawley rats given a single gavage dose of 50 or 150 mg RES/kg body weight (mg/kg), the time at which maximal plasma concentrations were reached (T_max_) was ≤1 hour.^57,58^ After repeated dosing (daily for 14 days) in the CD rats, the T_max_ decreased to 0.25 hours in the 50 mg/kg/day group but increased to 2 hours in the 150 mg/kg/day group.^57^ The National Toxicology Program (NTP) previously investigated the toxicokinetic (TK) behavior of RES in male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (312.5, 625, or 1,250 mg/kg) and B6C3F1/N mice (625, 1,250, or 2,500 mg/kg) following a single intravenous or gavage administration.^59^ In both male and female rats and mice, T_max_ was predicted by modeling to be ≤4.4 hours, with observed values ranging from 1.5 to 8 hours. Secondary peaks in the plasma concentration-time curves were observed, suggesting enterohepatic recirculation.^59^ The plasma elimination half-life in male and female rats for the two lower doses were 5.6–8.4 hours but increased to 17.7–22.1 hours in the 1,250 mg/kg/day dose group. In male and female mice, the elimination half-life ranged between 0.3 and 10.7 hours without any clear dose-related effect. Systemic exposure parameters maximum concentration (C_max_) and area under the concentration-time curve (AUC) increased linearly with the dose in both rats and mice. In general, the TK behavior of RES was similar between sexes.

The plasma elimination half-life found in previous NTP studies is similar to what has been reported in other studies. In male Wistar rats given red wine containing 6.5 mg/L of RES, the plasma elimination half-life was estimated to be 0.5 hours.^60^ Other studies in rats following oral administration of RES (50–150 mg/kg/day) report plasma elimination half-lives in the range of 1.8–11.8 hours.^57,58^ Unlike previous NTP studies in which the highest dose (i.e., 1,250 mg/kg) yielded longer half-lives in both mice and rats,^59^ Kapetanovic et al.^57^ reported that higher and repeated doses resulted in shorter half-lives. This discrepancy may be due to differences in doses used, 50–150 mg/kg/day versus 312.5–1,250 mg/kg/day.

Although RES is rapidly absorbed by the gastrointestinal tract in rodents, oral bioavailability of RES is low to moderate. In previous NTP studies, the oral bioavailability estimated was higher in rats (~12%–31%) compared to mice (~3%–6%).^59^ Other studies also report low oral bioavailability ranging from 18% to 38%,^57,58^ due to extensive first pass metabolism in the intestine and liver. Gestational transfer of RES has been observed in both Japanese macaques exposed to 0.37% RES via the diet during pregnancy^61^ and rats following exposure to 4 g/kg RES via the diet from gestation day (GD) 7 to GD 21.^62^

RES undergoes extensive phase II metabolism in the liver of rodents, producing sulfate and glucuronide conjugates such as trans-resveratrol-3-O-B-D-glucuronide (trans-R3G), trans-resveratrol-4-O-glucuronide, trans-resveratrol-diglucuronide, trans-resveratrol-3-O-sulfate (trans-R3S), and cis-resveratrol-3,4′-disulfate.^57,59,63-66^ Concentrations of these metabolites, particularly trans-R3G and trans-R3S, are generally higher than the concentration of the parent compound. Resveratrol metabolites tend to have similar half-lives to the parent compound in rodents.^57,59^ Some studies reviewed in Detampel et al.^67^ suggest RES inhibits phase I metabolism and induces phase II metabolism, indicating the potential for RES-drug interactions.

RES and its metabolites are present in the systemic circulation and are distributed widely to a variety of tissues in rodents including heart, lung, liver, kidney, brain, and spleen.^59,60,63,64,66,68,69^ Dermal administration of RES yielded a similar distribution profile of RES in tissues to that seen with oral administration.^70^ Tissue concentrations of RES are highly dependent on the expression of glucuronidating and sulfating enzymes, which can be tissue-specific, but also on how much is transported into cells.^71^ Resveratrol sulfates may be hydrolyzed to regenerate the parent compound by sulfatases.^71^ Thus, the amount of RES in tissues, and likewise RES elimination and metabolism, is a function of a complex interplay between metabolism and transport mechanisms. Excretion of RES and its metabolites is primarily through renal elimination. Concentrations of RES-derived radioactivity 18 hours postgavage was highest in the urine (3.3%) followed by feces (1.6%).^69^

In dogs following oral administration of 200, 600, or 1,200 mg/kg/day for 13 weeks, T_max_ of RES and metabolites ranged from 1 to 7 hours, with no apparent differences by dose.^72^ As observed with rats,^58,59^ secondary peaks in the plasma concentration-time curves were observed in some dogs, suggesting enterohepatic recirculation.^72^ In dogs, the half-life of RES was 2–4 hours.^72^ RES sulfate had a longer half-life than the parent compound in dogs, although the study was limited.^72^

### Humans

Studies in humans have found rapid absorption of orally administered RES. Absorption of 25 mg radiolabeled RES was 70%, with a plasma T_max_ reached in about 1 hour.^73^ Studies of single or repeated administration of 0.5–5 mg RES also reported rapid absorption of RES, with T_max_ in the range of 1–1.5 hours.^74,75^ As in rodents, enterohepatic recirculation has been observed 5–6 hours after dosing.^73,74^ In a study evaluating single and repeat dosing of 200 mg RES, T_max_ did not change with repeated dosing and the degree of accumulation was moderate with accumulation ratios (AUC of repeated dose to AUC of single dose) ranging from 1.44 to 2.09.^76^ In both studies, as in rats, bioavailability was low (<1%), likely due to the extensive metabolism of RES in the liver and intestine.^77^ Some studies have investigated how the bioavailability of RES changes depending on how it is consumed: as a pure compound, in grape juice or wine, or with certain foods.^78,79^ For instance, high lipid-content foods were found to decrease the bioavailability of a 2 g dose of RES,^80^ although this finding was not confirmed in another study evaluating RES consumed through red wine.^81^

Metabolism of RES in humans also is extensive, producing sulfate and glucuronic acid conjugates similar to those found in rodents, although at different proportions.^74,75,79,82,83^ In humans, sulfate conjugates are more prominent,^55^ while in rodents glucuronide conjugates are more common.^55,59^ Additionally, resveratrol-4′-O-glucuronide has been measured in human plasma after dosing, but much less is found in rodent plasma and tissues. A comparative study of glucuronidation in human, dog, rat, and mouse liver microsomes found higher rates of glucuronidation and higher production of resveratrol-3-O-glucuronide and insignificant formation of resveratraol-4-O-glucuronide in rodent microsomes compared to human and dog microsomes after incubation with 100 µM RES.^71^ Lastly, differences in microbiota or anatomical differences in the intestine may lead to variations in microbially derived RES metabolites.^63^

Data on the tissue distribution of RES and its metabolites in humans are limited. One study reported RES and metabolites (resveratrol-3-O-glucuronide, resveratrol-4′-O-glucuronide, resveratrol-3-O-sulfate, resveratrol-4′-O-sulfate, resveratrol disulfate, and resveratrol sulfate glucuronide) in samples of normal and neoplastic colon tissue in colorectal cancer patients who consumed 500–1,000 mg RES per day for 8 days.^83^ While mean RES concentrations in neoplastic colon tissues from patients given 1,000 mg for 8 days were 94 nmol per gram,^83^ mean concentrations of RES in hepatic metastases from colorectal cancer patients on a similar RES treatment regimen (5 g per day for 10–21 days) were much lower (4.8 nmol per gram).^84^

Similar to what has been observed in animals, the plasma half-life of RES in humans ranges from 1 to 11 hours with minimal dose dependence.^74-76,84^ In a small study of elderly and young male and female participants (n = 6 per age group) given 200 mg RES once on the first day and then three times daily for 3 more days, the half-life of RES ranged from 2.5 to 4.7 hours.^76^ No significant differences in half-life were observed due to age, sex, or dosing frequency.^76^ Other human studies found the half-life of RES to be 2–9 hours, with differences varying with increasing dose (0.5 to 5 mg RES) or dose frequency (single versus repeated dose for 28 days).^74,75^ In those studies, RES metabolites in plasma tended to be similar to those of the parent compound.^74,75^

As in experimental animals, RES and its metabolites are rapidly excreted in humans, primarily through the urine. Following a single oral dose of 0.5–5 g to healthy volunteers, 77% of the urinary metabolites of RES were recovered within 4 hours after dosing.^74^ In that study, fecal concentrations of RES metabolites were less than that of RES, which is consistent with enterohepatic recirculation.^74^

## Toxicity

### Experimental Animals

Animal studies show minimal toxicity associated with oral RES administration. A 28-day study in Wistar Han rats given RES via diet (0, 50, 150, 500 mg/kg/day) showed no exposure-related effects on body weight, clinical signs, hematology, clinical chemistry, or histopathology at any exposure concentration.^85^ Another 28-day study in CD^®^ Virus Antibody Free (VAF) rats given ≤3,000 mg/kg/day found slight hemolytic anemia in male rats, with no histological correlate, which resolved after a 4-week recovery period.^86,87^ A 90-day study in Wistar Han rats established a no-observed-adverse-effect level (NOAEL) of 750 mg/kg/day.^85^ In CD (Crl:CD^®^[SD]IGS) rats given 200, 400, or 1,000 mg/kg/day via gavage for 90 days, the middle and high female dose groups had significantly decreased mean body weight gains relative to the vehicle control group; no body weight changes were observed in males.^88^ Additionally, there were significant increases in bilirubin at the high dose and hepatomegaly at the middle and high doses in both sexes. No dose-related changes in hematology, clinical chemistry, coagulation parameters, other organ weights, or histopathology were observed. Oral dosing in rats for 6 months resulted in decreased body weights and discolored feces at the highest dose (2,000 mg/kg/day); the NOAEL in this and other studies was 300 mg/kg/day.^86,87^ Additional studies have reported even higher NOAELs (e.g., 1,000 mg/kg/day).^89^ At higher doses (>2,000 mg/kg/day), nephrotoxicity has been observed in male and female CD^®^ VAF rats.^86^

In male and female dogs, RES-related effects involved only abnormally colored feces during dosing; there were no dose-related changes in body weight, organ weight, or histopathological evaluations or any cardiotoxic effects.^87^ The NOAEL in dogs was 300 mg/kg/day. A separate 90-day oral toxicity study in dogs demonstrated no dose‐related mortality, clinical signs of toxicity, or gross pathology at 200, 600, or 1,200 mg/kg/day.^88^ However, body weights for both male and female dogs were significantly decreased at the highest dose, which was associated with decreased feed consumption. For this reason, the NOAEL for RES in dogs was 600 mg/kg/day.^88^ RES did not cause skin or eye irritation in male and female New Zealand white rabbits.^85^

### Humans

In humans, RES appears to be generally well tolerated. Clinical trials with low doses of RES show no adverse effects. At higher doses (≥0.5 g/day), the most common adverse effects were gastrointestinal (abdominal pain, nausea, flatulence, diarrhea).^75,90,91^

## Reproductive and Developmental Toxicity

### Experimental Animals

A limited number of studies have evaluated the effects of RES exposure in utero and its potential reproductive toxicity. In developing chick embryos of white Leghorns, RES (1, 10, 25, 50, or 100 μg/disk [0.004, 0.044, 0.11, 0.22, or 0.438 μmol/disk] incubated for 48–72 hours) induced avascular zones in the developing chorioallantoic membrane.^92^ RES did not elicit any effects on implantation number, resorptions, live young, or pre- and postimplantation losses in pregnant Sprague Dawley rats consuming 0, 120, 300, or 750 mg RES/kg/day in the diet from gestation day (GD) 5 through 20.^85^ Furthermore, uterine, placental, litter, and fetal weights were similar and there were no fetal abnormalities. Thus, the NOAEL for maternal toxicity and embryofetal development in Sprague Dawley rats in this study was the highest dose tested, 750 mg/kg/day. Another reproductive toxicity study was conducted in rats administered 300, 1,000, or 3,000 mg/kg/day via oral gavage from GD 7 through GD 17. While some (5 out of 25) dams were euthanized due to adverse clinical conditions, there were no effects on the fetuses at any dose. The maternal NOAEL was 300 mg/kg/day and the developmental NOAEL was 1,000 mg/kg/day.^87^ A study in CD-1 (ICR) mice exposed to concentrations of RES similar to concentrations found in wine (3 mg/L in water) also found no effect on litter size or sex ratio.^93^ RES has been reported, however, to impair morphogenesis in the P19C5 embryoid body murine morphogenesis assay via changes in Wnt3a, Tbx6, and Cyp26a1 gene expression.^94^

The effects of RES on reproductive organs are varied. In one study, Sprague Dawley rats exposed to 120, 300, or 750 mg/kg/day via the diet for 90 days did not show changes in sperm count and quality, ovarian morphology, estrous cycling, or reproductive organ histopathology.^85^ In CD-1 (ICR) mice, there was no effect of exposure to drinking water containing 3 mg/L RES for 90 days on body weight, sperm count, sperm morphology, or ovary morphology but there was a decrease in seminal vesicle and ovary weight compared to control animals.^93^ On the other hand, administration of 20 mg/kg/day via gavage for 90 days in Sprague Dawley rats resulted in reduced diameter of seminiferous tubules, increased density of seminiferous tubules, and increased sperm count and plasma concentrations of luteinizing hormone, follicle stimulating hormone, and testosterone.^95^ RES has been reported to bind to estrogen receptor (ER)α and ERβ with similar affinity, and is mitogenic in ERα and β transfected CHO-K1 cells, and the ER positive (ER+) cell lines MCF-7 and T47T.^96,97^

RES has been studied as a protective agent against chemical-, disease-, or age-related impairments in reproductive organs. Due in part to its antioxidant properties, RES has been shown to be protective against chemical-induced damage to the ovaries and spermatogonia.^98-102^ RES improved estrus cyclicity in rat models of polycystic ovary syndrome (PCOS), increased the ovarian follicle reserve, and extended ovarian life span in rats (reviewed in Ortega and Duleba^103^). In vitro incubation with RES induced maturation and blastocyst formation in oocytes from aged mice.^104^ Additionally, RES modulated the insulin signaling pathways in theca-interstitial cells that may prevent the theca-interstitial cell hyperplasia seen in PCOS.^105^

### Humans

The literature contains no studies on the reproductive and developmental toxicity of RES in humans. In a study evaluating RES as a protective agent for reproductive function, hyperandrogenic PCOS patients took 1,500 mg/day of RES for 3 months and exhibited decreased testosterone levels and increased insulin sensitivity.^106^ Incubation of oocytes from women aged 38–45 years in RES-containing media improved oocyte quality.^104^ These improvements were attributed to increased mitochondrial function and improved spindle and chromosomal formation in the oocytes.

## Immunotoxicity

A previous NTP study found no significant toxicity on innate or adaptive immune system function after oral gavage exposure of male B6C3F1/N mice to ≤2,500 mg/kg/day resveratrol for 28 days.^107^ An independent safety study found no evidence of sensitization induced by RES in the local lymph node assay.^85^ Other studies have described immunomodulatory effects of RES, both experimentally and in humans,^35,108-110^ primarily for its use as a preventive agent against chronic, immune-related diseases rather than in the context of evaluating toxicity.

## Carcinogenicity

The literature contains no studies on the carcinogenicity of RES in animals or humans. One study assessed the carcinogenicity of RES in TSG-p53^+/-^ (heterozygous p53 knockout; p53^+/-^) mice. There were no increases in the incidence of benign or malignant neoplasms in TSG-p53^+/-^ mice after 6 months of exposure via oral gavage at 1,000, 2,000, or 4,000 mg/kg/day, but urothelial hyperplasia was observed at 2,000 and 4,000 mg/kg/day.^89^ In this study, there was high mortality in the 2,000 and 4,000 dose groups (40% and 70%, respectively), likely due to gastrointestinal test article impaction.^89^

## Genetic Toxicity

Although RES has been investigated for antioxidant and antigenotoxic effects, several studies (described below) indicate it has genotoxic activity in vitro, which may be partially dependent on forming a complex with copper and oxygen. However, the few in vivo studies reported for this compound suggest that RES does not appear to be genotoxic.

RES was reported as negative in Salmonella typhimurium tester strains TA98 and TA100, and in Escherichia coli WP2 uvrA, when tested at several concentrations ranging from 0.02 to 5,000 μg/plate in the absence or presence of rat metabolic liver enzymes (S9 mix).^111^ A highly purified preparation of RES, called resVida^®^, was also reported as negative in S. typhimurium tester strains TA98, TA100, TA1535, TA1537, and E. coli WP2 uvrA (pKM101), when tested at ≤5,000 μg/plate in the absence or presence of rat S9 mix.^85^

In cell culture studies conducted by Matsuoka et al.,^111^ exposure to 20 μg/mL resveratrol for 24–48 hours increased the frequency of micronuclei in Chinese hamster lung (CHL) fibroblasts. Chromosomal aberrations, primarily chromatid breaks and exchanges, increased when CHL fibroblasts were exposed to 10 μg/mL resveratrol for 48 hours or to 20 μg/mL resveratrol for 54 hours. Exposure to 10 μg/mL resveratrol for 48 or 72 hours also changed the modal number of chromosomes in metaphase spreads from these cells, suggesting that RES may have an aneugenic effect.

The genotoxicity of RES was also evaluated in Chinese hamster V79 lung fibroblasts and L5178Y Tk^+/-^ mouse lymphoma cells by Schmitt et al.^112^ V79 cells were exposed to 100 μM RES for 6 hours, washed, and then evaluated for micronuclei every hour from 2 to 18 hours after exposure. Micronuclei were increased by approximately 10-fold at time points ranging from 14 to 18 hours. L5178Y Tk^+/-^ cells were exposed to several concentrations of RES, ranging from 1 to 60 μM, for 4 hours. Cells were washed and allowed to grow for another 20 hours before harvest. Dose-dependent induction of micronuclei was observed, with a fivefold induction at 60 μM. Cells from this experiment were also evaluated for kinetochore-positive micronuclei, aberrant spindle morphology, and displacement of chromosomes from metaphase rings, which increased by 2.3-, 2.9-, and 1.7-fold, respectively, at 60 μM, suggesting that RES might induce micronuclei by an aneugenic mode-of-action. RES (≤200 μM) did not affect microtubule assembly in a cell-free tubulin polymerization assay, however.

Human colonic epithelial NCM460 cells were exposed to 0, 0.01, 0.1, 1, 10, or 100 μM RES for 24 hours and evaluated in a cytokinesis-block micronucleus assay.^113^ A U-shaped curve was observed for micronuclei at concentrations from 0 to 10 μM, with levels of micronuclei dropping below control levels from 0.01 to 0.1 μM and increasing to control levels from 1 to 10 μM, with a modest induction of micronuclei above control levels at 100 μM.

Several studies have investigated the mechanisms by which RES causes genotoxicity in vitro. Using a set of six analogues of RES that differed in the number and placement of hydroxy groups, Matsuoka et al.^114^ showed that the 4’-hydroxy group was necessary for the genotoxic effects of RES in the micronucleus assay and chromosomal aberration assay when conducted using CHL fibroblasts. For each experimental endpoint, CHL fibroblasts were exposed to concentrations of RES analogues ranging from 2.5 to 20 μg/mL for 24 or 48 hours, or to 10 μg/mL of RES for 48 hours for comparison. In a study by Liu et al.,^115^ a panel of isogenic DT40 chicken B-lymphoma cells deficient for genes involved in different DNA repair pathways were compared to wildtype DT40 cells when exposed to concentrations of RES ranging from 5 to 20 µM for 72 hours. This panel indicated that genes related to DNA single strand break repair (Parp1), base excision repair (Polβ), homologous recombination (Brca1 and Brca2), and translesion synthesis (Rev3 and Rad18) were required to survive exposure to RES, whereas cells did not depend on nucleotide excision repair (Xpa) and nonhomologous end joining repair (Ku70) for survival. Furthermore, deficiency for Parp1 or Polβ modestly increased sensitivity to RES-dependent induction of γ-H2AX (a biomarker of double strand DNA breaks) and chromosomal aberrations compared to WT DT40 cells. Biochemical studies indicate that RES forms a copper-peroxide complex that may target reactive oxygen to DNA, resulting in DNA damage.^116^ In the presence of cupric ions (Cu^2+^) and oxygen, the dihydroxylated benzene ring of RES is converted to a trihydroxylated benzene ring complexed with Cu^2+^, oxygen, and water. This complex promoted cleavage of DNA in a plasmid-based DNA cleavage assay when present at concentrations as low as 1 μM. This effect was not observed with other metal ions, such as Mg^2+^, Mn^2+^, Zn^2+^, Ni^2+^, Co^2+^, or Fe^3+^.

Although RES has been shown to cause DNA damage in vitro, it was not genotoxic in the few in vivo studies that have been reported for this compound. Micronuclei were not induced in polychromatic erythrocytes (PCEs) obtained from the bone marrow of male Swiss albino mice when evaluated 24 hours after exposure to 0, 6.25, 12.5, 25, 50, or 100 mg/kg RES by gavage.^117^ No significant increases in micronucleated PCEs, and no apparent toxicity to PCEs, were observed in bone marrow from male Sprague Dawley rats administered 0, 500, 1,000, or 2,000 mg/kg/day resVida^®^ by gavage on 2 consecutive days (24 hours apart).^85^ resVida^®^ was present in plasma and widely distributed among various organs in male Sprague Dawley rats, although bone marrow was not specifically assessed for the presence of resVida^®^.^85^

## Study Rationale

RES was nominated by the National Institute of Environmental Health Sciences for toxicological evaluation by NTP due to its widespread use as a dietary supplement and insufficient information on its potential toxicity and carcinogenicity. In particular, data were lacking on effects associated with perinatal exposure and effects at the doses being investigated for therapeutic purposes. Because exposure to RES occurs primarily through ingestion, oral gavage was the selected route of administration.