# Appendix F Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-102.

## F.1 Two-week Study in F344/NTac Rats

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P22 – Cause of Death Summary

P40 – Survival Curves

PA06 – Organ Weights Summary

## F.2 Two-week Study in F344/NTac Rats – Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

## F.3 Two-week Study in B6C3F1/N Mice

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P22 – Cause of Death Summary

P40 – Survival Curves

PA06 – Organ Weights Summary

## F.4 Two-week Study in B6C3F1N Mice – Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

## F.5 Perinatal and Three-month Study – Wistar Han Rats

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E12 – Animal History

Gestational Body Weight Changes (g)

Gestational Body Weights (g)

Lactational Body Weight Changes (g)

Lactational Body Weights (g)

Live Litter Size and Survival

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P10 – Statistical Analysis of Non-Neoplastic Lesions – Litter based

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PA48 – Summary of Tissue Concentration

PND 1 Data

Pup Body Weights (g)

R02 – Reproductive Performance Summary

R06 – Andrology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

## F.6 Perinatal and Three-month Study in Wistar Han Rats – Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Andrology Data

Individual Animal Clinical Chemistry Data

Individual Animal Dam ID and Pup ID Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

## F.7 Three-month Study – B6C3F1/N Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA43 – Hematology Summary

R06 – Andrology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

## F.8 Three-month Study in B6C3F1/N Mice – Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Andrology Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## F.9 Genetic Toxicology

### F.9.1 Wistar Han Rats

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### F.9.2 B6C3F1/N Mice

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### F.9.3 Bacterial Mutagenicity

G06 – Ames Summary Data