# Appendix D Trans-resveratrol Internal Dose Assessment

## D.1 Sample Collection

Biological samples were collected from Wistar Han rats in the 0, 78, 312.5, and 1,250 mg/kg/day trans-resveratrol (RES) dose groups and stored at approximately −20°C before shipment on dry ice to RTI International (Research Triangle Park, NC) for analysis to confirm internal concentration. On gestation day (GD) 18, blood was collected from the retroorbital sinus of three randomly selected dams from each dose group at 30 minutes, 60 minutes, or 90 minutes after RES administration (nine dams per dose group in total). Animals were anesthetized with a carbon dioxide/oxygen mixture and blood was collected into tubes containing sodium heparin, centrifuged, and the plasma harvested. The dams were then humanely euthanized with carbon dioxide, and the fetuses were removed and individually flash frozen in liquid nitrogen. On postnatal day (PND) 4, 10 male and 10 female randomly selected standardized pups for each dose group were humanely euthanized by decapitation, placed into individual vials (one pup per vial), and flash frozen in liquid nitrogen. On PND 21, blood was collected via cardiac puncture from five male and five female randomly selected, standardized pups for each dose group. Animals were first anesthetized with a carbon dioxide/oxygen mixture and blood was then collected into tubes containing lithium heparin, centrifuged, and the plasma harvested. After blood collection, the pups were humanely euthanized by carbon dioxide inhalation overdose and were disposed of without further evaluation. At study termination, blood was collected from the retroorbital site of five randomly selected animals per sex for each dose group. Animals were anesthetized with a carbon dioxide/oxygen mixture and blood was collected into tubes containing sodium heparin, centrifuged, and the plasma harvested.

## D.2 Sample Analysis

Concentrations of RES in rat blood plasma and homogenized fetal tissues were quantified using a validated analytical method; method validation data are given in Table D-1. All sample handling and analysis was performed under yellow light to minimize the conversion of trans-resveratrol to the cis- form.

Plasma samples were allowed to equilibrate to room temperature and were mixed well prior to removing sample aliquots for analysis. A 50 μL aliquot was transferred from each sample to a 1.5 mL microcentrifuge tube to which 50 μL of methanol was added, followed by 20 μL of internal standard (IS) solution (100 ng 2′,4′-dihydroxypropiophenone/mL methanol) and 200 μL of acetonitrile. All tubes were mixed, then centrifuged for approximately 20 minutes at 0°C. Aliquots of supernatant were transferred to glass autosampler vials for analysis.

Fetuses were removed from freezer storage, and a weight was recorded for a single representative fetus sample in each litter. The samples were pooled by litter into wide-mouth glass bottles, allowed to equilibrate to room temperature, and then homogenized. From each pooled sample an approximately 0.5 g aliquot was transferred to a 20 mL scintillation vial to which a 20 μL aliquot of methanol was added followed by 20 µL of IS solution and 300 μL of deionized water. A 1 mL aliquot of methanol was added to each vial. The vials were mixed, sonicated for approximately 5 minutes, and then centrifuged for approximately 30 minutes. Each supernatant was decanted and filtered into 1.5-mL microcentrifuge tubes, equilibrated in liquid nitrogen, and then centrifuged for approximately 20 minutes at approximately −9°C. Aliquots of supernatant were transferred to glass autosampler vials for analysis.

Each pup sample was removed from freezer storage and the weights of individual samples were recorded. Each sample was then equilibrated in liquid nitrogen, placed into double plastic bags, shattered, transferred to an individual wide-mouth glass bottle, allowed to thaw to room temperature, and then homogenized. For each pup sample, an approximately 0.5 g aliquot of homogenate was transferred to a 20 mL scintillation vial to which was added a 20 μL aliquot of methanol followed by 20 µL of IS solution and 300 μL of deionized water. A 1 mL aliquot of methanol was added to each vial. The vials were mixed, sonicated for approximately 5 minutes, and then centrifuged for approximately 30 minutes. Each supernatant was decanted and filtered into 1.5 mL microcentrifuge tubes, equilibrated in liquid nitrogen, then centrifuged for approximately 20 minutes at approximately −9°C. Aliquots of supernatant were transferred to glass autosampler vials for analysis.

## D.3 Instrumentation and Quantitation

Samples were analyzed using a Waters Acquity (Milford, MA) ultra-performance liquid chromatograph (UPLC) coupled with a 4000 QTRAP hybrid triple quadrupole/linear ion trap mass spectrometer with a TurboSpray source (Sciex, Framingham, MA). Chromatographic analysis was performed using a Waters Acquity UPLC HSS T3 column (100 mm × 2.1 mm internal diameter [ID], 1.8 µm particle size) with guard column (5 mm × 2.1 mm ID, 1.8 µm particle size). Two μL of sample were injected onto the column and elution was achieved at ambient temperature using a binary gradient and a flow rate of 0.3 mL/minute. The mobile phases consisted of: (A) 5 mM ammonium acetate in water with 2% (v/v) isopropyl alcohol (pH unadjusted) and (B) methanol with 2% (v/v) isopropyl alcohol. The gradient was 15% B for 2 minutes, 15% to 65% B from 2 to 15 minutes, then to 95% B for 0.5 minutes. The electrospray ion source was operated in negative ion mode with a voltage of −3,700 V and source temperature of 600°C. The collision gas was high, the curtain gas was 15 psi, the nebulizer gas was 60 psi, the auxiliary gas was 40 psi, and the interface heater was on. The selected multiple reaction monitoring (MRM) transitions were m/z 227 → 185 for RES, and m/z 165 → 109 for 2′,4′-dihydroxypropiophenone (IS). The optimized compound-dependent parameters for RES were: declustering potential (DP) = −65 V; entrance potential (EP) = −10 V; collision energy (CE) = −26 V; and collision cell exit potential (CXP) = −15 V.

The performance of the calibration curve was evaluated prior to the analysis of each sample set. A successful calibration was indicated by the following: correlation coefficient (r) ≥ 0.99; relative standard deviation (RSD) less than or equal to ±15% (except at the limit of quantitation [LOQ] where RSD is less than or equal to ±20%); relative error (RE) less than or equal to ±15% (except at the LOQ where RE is less than or equal to ±20%).

Analytical method validation data for resveratrol-3-O-B-D-glucuronide (trans-R3G) and resveratrol-3-O-sulfate (trans-R3S) are given in Table D-2 and Table D-3, respectively. Samples were prepared and analyzed as above for RES except that the selected MRM transitions used for trans-R3G was m/z 403 → 227 and for trans-R3S was m/z 307 → 227. The optimized compound-dependent mass spectrometer parameters for trans-R3G and trans-R3S were: DP = −55 V; EP = −10 V; CE = −34 V; and CXP = −11 V.

Table D-1 Analytical Method Validation and Stability Data for Trans-resveratrol in Wistar Han Plasma, Pup Homogenate, and Fetuses

Validation Parameter | Rat Plasma^a^ | Rat Pup^a^
Matrix Concentration Range (ng/mL or ng/g) | 5–5,000 | 10–2,500
LOQ (ng/mL or ng/g) | 5.06 | 10.0
LOD (ng/mL or ng/g) | 1.70 | 2.25
Correlation Coefficient (r) | ≥0.99 | ≥0.99
Recovery (%)^b^ | 105 | 70.4
Precision and Accuracy^c,d^
Intra-day % RSD | ≤7.5 | ≤2.0
Intra-day % RE | ≤ ± 6.2 | ≤ ± 7.3
Inter-day % RSD | ≤7.9 | ≤8.4
Inter-day % RE | ≤ ± 5.8 | ≤ ± 5.2
Dilution Verification^e^
% RSD | NA | NA
% RE | NA | NA
Extract Stability (Average % RE)^c,d^
Ambient storage (RT, ~7 days) | −10.0 to −4.5 | −2.8 to 0.0
Refrigerated storage (4°C, ~7 days) | −4.9 to 4.9 | −8.6 to −1.9
Matrix Stability (Average % RE)^c,f^
Freeze-thaw (3 cycles, over 5–7 days) | −8.7 to −0.1 | −12 to −4.6
Frozen matrix (−80°C for up to ~60 days) | 1.0 | 0.7
Secondary Matrix Evaluation | Male Rat Plasma | Fetus Homogenate
Precision (% RSD)^c^ | ≤7.3 | ≤3.0
Accuracy (% RE)^c^ | ≤ ± 14.5 | ≤ ± 9.6

LOQ = lower limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error; NA = not applicable; RT = room temperature.

^a^ Method was fully validated in female Wistar Han rat plasma and pup homogenate using matrix standard curves and cross-validated in rat fetuses using 3 concentrations (100, 200, and 1,000 ng/g) of quality control (QC) samples prepared in rat fetus homogenate and analyzed using the pup matrix curve.

^b^ Estimated by comparing the response of the matrix sample to the response of the solvent sample.

^c^ Precision was estimated as % RSD. Accuracy was estimated as average % RE.

^d^ Determined for four replicate QC samples at three concentrations: 20, 102, and 2,040 ng/mL for rat plasma and for three replicate QC samples at three concentrations: 100, 200, and 1,000 ng/g in pup homogenate.

^e^ NA = validation test not performed.

^f^ Study sample matrices were assessed using four replicate QC samples at three concentrations: 20, 102, and 2,040 ng/mL for rat plasma and for three replicate QC samples at three concentrations: 100, 200, and 1,000 ng/g in pup homogenate evaluated using freshly extracted standards and stored standard extracts.

Table D-2 Analytical Method Validation and Stability Data for Trans-resveratrol-3-O-B-D-glucuronide in Wistar Han Plasma, Pup Homogenate, and Fetuses

Validation Parameter | Rat Plasma^a^ | Rat Pup^a^
Matrix Concentration Range (ng/mL or ng/g) | 96.5–11,600 | 96.0–12,000
LOQ (ng/mL or ng/g) | 96.5 | 96.0
LOD (ng/mL or ng/g) | 30.7 | 27.3
Correlation Coefficient (r) | ≥0.99 | ≥0.99
Recovery (%)^b^ | 111 | 76.8
Precision and Accuracy^c,d^
Intra-day % RSD | ≤5.7 | ≤8.6
Intra-day % RE | ≤ ± 5.0 | ≤ ± 3.3
Inter-day % RSD | ≤8.9 | ≤5.7
Inter-day % RE | ≤ ± 3.9 | ≤ ± 3.0
Dilution Verification
% RSD | 6.8 | 10
% RE | −12.3 | −20
Extract Stability (Average % RE)^c,d,e^
Ambient storage (RT, ~7 days) | NA | NA
Refrigerated storage (4°C, ~7 days) | NA | NA
Matrix Stability (Average % RE)^c,f^
Freeze-thaw (3 cycles, over 5–7 days) | −18.2 to −3.3 | −12 to 12
Frozen matrix (−80°C for up to ~60 days) | −10.2 | NA^e^
Secondary Matrix Evaluation | Male Rat Plasma^e^ | Fetus Homogenate
Precision (% RSD)^c^ | NA | ≤4.1
Accuracy (% RE)^c^ | NA | ≤ ± 13

LOQ = lower limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error; NA = not applicable; RT = room temperature.

^a^ Method was fully validated in female Wistar Han rat plasma and pup homogenate using matrix standard curves and cross-validated in rat fetuses using 3 concentrations (240, 2,400, and 6,000 ng/g) of quality control (QC) samples prepared in rat fetus homogenate and analyzed using the pup matrix curve.

^b^ Estimated by comparing the response of the matrix sample to the response of the solvent sample.

^c^ Precision was estimated as % RSD. Accuracy was estimated as average % RE.

^d^ Determined for four replicate QC samples at three concentrations: 241, 1,930, and 4,830 ng/mL for rat plasma and for three replicate QC samples at three concentrations: 240, 2,400, and 6,000 ng/g in pup homogenate.

^e^ NA = validation test not performed.

^f^ Study sample matrices were assessed using four replicate QC samples at three concentrations: 241, 1,930, and 4,830 ng/mL for rat plasma and for three replicate QC samples at three concentrations: 240, 2,400, and 6,000 ng/g in pup homogenate evaluated using freshly extracted standards and stored standard extracts.

Table D-3 Analytical Method Validation and Stability Data for Trans-resveratrol-3-O-sulfate in Wistar Han Plasma, Pup Homogenate, and Fetuses

Validation Parameter | Rat Plasma^a^ | Rat Pup^a^
Matrix Concentration Range (ng/mL or ng/g) | 5.03–12,100 | 99.2–12,400
LOQ (ng/mL or ng/g) | 5.03 | 99.2
LOD (ng/mL or ng/g) | 1.48 | 17.5
Correlation Coefficient (r) | ≥0.99 | ≥0.99
Recovery (%)^b^ | 115 | 109
Precision and Accuracy^c,d^
Intra-day % RSD | ≤12 | ≤4.3
Intra-day % RE | ≤ ± 11.1 | ≤ ± 5.2
Inter-day % RSD | ≤12 | ≤9.4
Inter-day % RE | ≤ ± 10.3 | ≤ ± 4.3
Dilution Verification
% RSD | 11 | NA^e^
% RE | −3.0 | NA^e^
Extract Stability (Average % RE)^c,d,e^
Ambient storage (RT, ~7 days) | NA | NA
Refrigerated storage (4°C, ~7 days) | NA | NA
Matrix Stability (Average % RE)^c,f^
Freeze-thaw (3 cycles, over 5–7 days) | −5.7 to 4.1 | −6.0 to 2.3
Frozen matrix (−80°C for up to ~60 days) | 0.7 | −10
Secondary Matrix Evaluation | Male Rat Plasma^e^ | Fetus Homogenate
Precision (% RSD)^c^ | NA | ≤3.4
Accuracy (% RE)^c^ | NA | ≤ ± 17

LOQ = lower limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error; NA = not applicable; RT = room temperature.

^a^ Method was fully validated in female Wistar Han rat plasma and pup homogenate using matrix standard curves and cross-validated in rat fetuses using 3 concentrations (240, 2,400, 6,000 ng/g) of quality control (QC) samples prepared in rat fetus homogenate and analyzed using the pup matrix curve.

^b^ Estimated by comparing the response of the matrix sample to the response of the solvent sample.

^c^ Precision was estimated as % RSD. Accuracy was estimated as average % RE.

^d^ Determined for four replicate QC samples at three concentrations: 20, 503, and 3,020 ng/mL for rat plasma and for three replicate QC samples at three concentrations: 240, 2,400, and 6,000 ng/g in pup homogenate.

^e^ NA = validation test not performed.

^f^ Study sample matrices were assessed using four replicate QC samples at three concentrations: 20, 503, and 3,020 ng/mL for rat plasma and for three replicate QC samples at three concentrations: 240, 2,400, and 6,000 ng/g in pup homogenate evaluated using freshly extracted standards and stored standard extracts.