# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 Rat and NTP-2000 Rat and Mouse Ration

Table B-1 Ingredients of NIH-07 Rat Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 24.25
Wheat Middlings | 10.0
Oat Hulls | 0.0
Alfalfa Meal (Dehydrated, 17% Protein) | 4.0
Purified Cellulose | 0.0
Soybean Meal (47% Protein) | 12.0
Fish Meal (62% Protein) | 10.0
Corn Oil (Without Preservatives) | 0.0
Soy Oil (Without Preservatives) | 2.5
Dried Brewer’s Yeast | 2.0
Calcium Carbonate (USP) | 0.5
Vitamin Premix^a^ | 0.25
Mineral Premix^b^ | 0.15
Calcium Phosphate, Dibasic (USP) | 1.25
Sodium Chloride | 0.5
Choline Chloride (70% Choline) | 0.10
Dried Skim Milk | 5.00
Dried Molasses | 1.50
Corn Gluten Meal (60% Protein) | 3.00
Methionine | 0.0

USP = United States Pharmacopeia.

^a^ Wheat middling as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 6,062 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 5,070 IU | D-activated animal sterol
Vitamin K | 3.1 mg | Menadione sodium bisulfite complex
Vitamin E | 22 IU | α-Tocopheryl acetate
Niacin | 33 mg | –
Folic Acid | 2.4 mg | –
d-Pantothenic Acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg | –
Thiamine | 11 mg | Thiamine mononitrate
B_12_ | 50 µg | –
Pyridoxine | 6.5 mg | Pyridoxine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 2.0 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NIH-07 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 24 | – | 1
Crude Fat (% by Weight) | 5 | – | 1
Crude Fiber (% by Weight) | 3.6 | – | 1
Ash (% by Weight) | 6.77 | – | 1
Amino Acids (% of Total Diet)
Arginine | 1.380 ± 0.06 | 1.3–1.49 | 10
Cystine | 0.322 ± 0.031 | 0.274–0.372 | 10
Glycine | 1.150 ± 0.070 | 1.06–1.31 | 10
Histidine | 0.518 ± 0.024 | 0.497–0.553 | 10
Isoleucine | 0.984 ± 0.024 | 0.952–1.03 | 10
Leucine | 2.018 ± 0.067 | 1.93–2.13 | 10
Lysine | 1.243 ± 0.051 | 1.13–1.32 | 10
Methionine | 0.488 ± 0.016 | 0.468–0.515 | 10
Phenylalanine | 1.097 ± 0.022 | 1.07–1.12 | 10
Threonine | 0.918 ± 0.031 | 0.883–0.961 | 10
Tryptophan | 0.277 ± 0.020 | 0.265–0.326 | 10
Tyrosine | 0.860 ± 0.037 | 0.785–0.894 | 10
Valine | 1.134 ± 0.025 | 1.11–1.17 | 10
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.30 ± 0.219 | 1.99–2.59 | 10
Linolenic | 0.25 ± 0.275 | 0.217–0.296 | 10
Vitamins
Vitamin A (IU/kg) | 4,640 | – | 1
α-Tocopherol (ppm) | 6,704 ± 21,045 | 40.3–66,600 | 10
Thiamine (ppm)^a^ | 10.6 | – | 1
Riboflavin (ppm) | 14.47 ± 3.352 | 10.0–19.8 | 10
Niacin (ppm) | 99.33 ± 8.235 | 87.0–112.0 | 10
Pantothenic Acid (ppm) | 44.38 ± 3.806 | 38.2–51.1 | 10
Pyridoxine (ppm)^a^ | 12.876 ± 3.171 | 9.63–19.7 | 10
Folic Acid (ppm) | 2.482 ± 0.487 | 1.68–3.09 | 10
Biotin (ppm) | 0.3283 ± 0.172 | 0.0–0.638 | 10
B_12_ (ppb) | 49.4 ± 6.83 | 41.8–61.6 | 10
Choline (as chloride) (ppm) | 1,821.0 ± 197.5 | 1,570–2,200 | 10
Minerals
Calcium (%) | 1.150 | – | 1
Phosphorus (%) | 0.930 | – | 1
Potassium (%) | 0.830 ± 0.036 | 0.769–0.88 | 10
Chloride (%) | 0.652 ± 0.106 | 0.441–0.8 | 10
Sodium (%) | 0.378 ± 0.46 | 0.318–0.469 | 10
Magnesium (%) | 0.187 ± 0.014 | 0.17–0.218 | 10
Iron (ppm) | 385.1 ± 54.9 | 276.0–469.0 | 10
Manganese (ppm) | 90.81 ± 7.566 | 80.7–104.0 | 10
Zinc (ppm) | 64.15 ± 10.07 | 52.4–89.2 | 10
Copper (ppm) | 14.13 ± 2.57 | 11.9–21.1 | 10
Iodine (ppm) | 1.811 ± 0.992 | 0.54–3.45 | 10
Chromium (ppm) | 1.422 ± 0.934 | 0.277–3.89 | 10
Cobalt (ppm) | 0.5155 ± 0.267 | 0.01–0.963 | 10

^a^ As hydrochloride.

Table B-4 Contaminant Levels in NIH-07 Rat Ration

| Level | Number of Samples
Contaminants
Arsenic (ppm) | 0.46 | 1
Cadmium (ppm) | 0.11 | 1
Lead (ppm) | 0.11 | 1
Mercury (ppm) | 0.01 | 1
Selenium (ppm) | 0.46 | 1
Aflatoxins (ppb)^a^ | 5 | 1
Nitrate Nitrogen (ppm)^b^ | 14.2 | 1
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | 1
BHA (ppm)^a,c^ | <1.0 | 1
BHT (ppm)^a,c^ | <1.0 | 1
Aerobic Plate Count (CFU/gm) | <10 | 1
Coliform (MPN/gm) | <3 | 1
Escherichia coli (MPN/gm) | <10 | 1
Salmonella sp. (MPN/gm) | negative | 1
Total Nitrosamines (ppb)^d^ | 8.7 | 1
N-Ndimethylamine (ppb)^d^ | 4.4 | 1
N-Npyrrolidine (ppb)^d^ | 4.3 | 1
Pesticides (ppm)
α-BHC^a^ | <0.01 | 1
β-BHC^a^ | <0.02 | 1
γ-BHC^a^ | <0.01 | 1
δ-BHC^a^ | <0.01 | 1
Heptachlor^a^ | <0.01 | 1
Aldrin^a^ | <0.01 | 1
Heptachlor Epoxide^a^ | <0.01 | 1
DDE^a^ | <0.01 | 1
DDD^a^ | <0.01 | 1
DDT^a^ | <0.01 | 1
HCB^a^ | <0.01 | 1
Mirex^a^ | <0.01 | 1
Methoxychlor^a^ | <0.05 | 1
Dieldrin^a^ | <0.01 | 1
Endrin^a^ | <0.01 | 1
Telodrin^a^ | <0.01 | 1
Chlordane^a^ | <0.05 | 1
Toxaphene^a^ | <0.10 | 1
Estimated PCBs^a^ | <0.20 | 1
Ronnel^a^ | <0.01 | 1
Ethion^a^ | <0.02 | 1
Trithion^a^ | <0.05 | 1
Diazinon^a^ | <0.10 | 1
Methyl Chlorpyrifos | 0.0335 | 1
Methyl Parathion^a^ | <0.02 | 1
Ethyl Parathion^a^ | <0.02 | 1
Malathion | 0.043 | 1
Endosulfan I^a^ | <0.01 | 1
Endosulfan II^a^ | <0.01 | 1
Endosulfane Sulfate^a^ | <0.03 | 1

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

Table B-5 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middling as carrier.

^b^ Calcium carbonate as carrier.

Table B-6 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-7 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 15.05 ± 0.794 | 13.9–15.9 | 5
Crude Fat (% by Weight) | 8.32 ± 0.172 | 8.0–8.5 | 5
Crude Fiber (% by Weight) | 9.05 ± 0.400 | 8.64–9.73 | 5
Ash (% by Weight) | 5.24 ± 0.170 | 5.0–5.43 | 5
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.8 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.100 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.30 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 2,965 ± 40 | 2,350–3,510 | 5
Vitamin D (IU/kg)^a^ | 1,000 | – | –
α-Tocopherol (ppm) | 2,456 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^b^ | 6.83 ± 1.329 | 5.3–9.0 | 5
Riboflavin (ppm) | 8.17 ± 2.841 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^b^ | 9.75 ± 2.045 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.89 | 18.3–174 | 29
Choline (as chloride) (ppm) | 2,593 ± 633.8 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.926 ± 0.024 | 0.898–0.969 | 5
Phosphorus (%) | 0.570 ± 0.026 | 0.504–0.606 | 5
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.54 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.02 ± 1.04 | 0.33–3.97 | 28
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 27

^a^ From formulation.

^b^ As hydrochloride.

Table B-8 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.251 ± 0.020 | 0.220–0.277 | 5
Cadmium (ppm) | 0.064 ± 0.016 | 0.055–0.096 | 5
Lead (ppm) | 0.084 ± 0.006 | 0.075–0.090 | 5
Mercury (ppm) | 0.014 ± 0.005 | 0.01–0.02 | 5
Selenium (ppm) | 0.181 ± 0.014 | 0.165–0.198 | 5
Aflatoxins (ppb)^a^ | <5.0 | – | 5
Nitrate Nitrogen (ppm)^b^ | 19.13 ± 5.641 | 11.2–26.5 | 5
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 5
BHA (ppm)^a,c^ | <1.00 | – | 5
BHT (ppm)^a,c^ | <1.00 | – | 5
Aerobic Plate Count (CFU/gm) | <10.00 | – | 5
Coliform (MPN/gm) | <3.00 | – | 5
Escherichia coli (MPN/gm) | <10.0 | – | 5
Salmonella sp. (MPN/gm) | Negative | – | 5
Total Nitrosamines (ppb)^d^ | 6.9 ± 4.72 | 2.0–13.9 | 5
N-Ndimethylamine (ppb)^d^ | 1.7 ± 1.7 | 1.0–5.1 | 5
N-Npyrrolidine (ppb)^d^ | 5.4 ± 3.7 | 1.0–9.3 | 5
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 5
β-BHC^a^ | <0.02 | – | 5
γ-BHC^a^ | <0.01 | – | 5
δ-BHC^a^ | <0.01 | – | 5
Heptachlor^a^ | <0.01 | – | 5
Aldrin^a^ | <0.01 | – | 5
Heptachlor Epoxide^a^ | <0.01 | – | 5
DDE^a^ | <0.01 | – | 5
DDD^a^ | <0.01 | – | 5
DDT^a^ | <0.01 | – | 5
HCB^a^ | <0.01 | – | 5
Mirex^a^ | <0.01 | – | 5
Methoxychlor^a^ | <0.05 | – | 5
Dieldrin^a^ | <0.01 | – | 5
Endrin^a^ | <0.01 | – | 5
Telodrin^a^ | <0.01 | – | 5
Chlordane^a^ | <0.05 | – | 5
Toxaphene^a^ | <0.10 | – | 5
Estimated PCBs^a^ | <0.20 | – | 5
Ronnel^a^ | <0.01 | – | 5
Ethion^a^ | <0.02 | – | 5
Trithion^a^ | <0.05 | – | 5
Diazinon^a^ | <0.10 | – | 5
Methyl Chlorpyrifos | 0.074 ± 0.054 | 0.020–0.170 | 5
Methyl Parathion^a^ | <0.02 | – | 5
Ethyl Parathion^a^ | <0.02 | – | 5
Malathion | 0.065 ± 0.025 | 0.020–0.094 | 5
Endosulfan I^a^ | <0.01 | – | 5
Endosulfan II^a^ | <0.01 | – | 5
Endosulfane Sulfate^a^ | <0.03 | – | 5

All samples were irradiated.

BHA = butylated hydroxyanisole; BHC = hexachlorocyclohexane or benzene hexachloride; BHT = butylated hydroxytoluene; CFU = colony-forming units; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; MPN = most probable number; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.