# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Trans-resveratrol

Trans-resveratrol (RES) was obtained from Bayville Chemical Supply Co. Inc. (Deer Park, NY) in a single lot (156AB). Identity, purity, and stability analyses were conducted by the analytical chemistry lab at RTI International (Research Triangle Park, NC). Reports on analyses performed in support of the RES study are on file at the National Institute of Environmental Health Sciences.

RES lot 156AB is a fine off-white powder with a melting point of 253.5°C. The identity of lot 156AB was evaluated using Fourier transform infrared (FT-IR) spectroscopy and ^1^H nuclear magnetic resonance (NMR) spectroscopy. Low-resolution mass spectrometry and high-resolution mass spectrometry were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) and the University of South Carolina (Columbia, SC), respectively. The FT-IR and ^1^H NMR spectra (Figure A-1 and Figure A-2) were consistent with the structure of RES, although no reference spectra were available. The low- and high-resolution mass spectra were consistent with the mass and structure of resveratrol.

Purity evaluation using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection was conducted with two different columns (Table A-1, Systems A and B). No impurities were identified using HPLC/UV, which could indicate that the minor diethyl ether and hexane impurities were eluted in the solvent front. Additionally, the presence of the cis-isomer of RES within the lot was evaluated using HPLC with a photodiode array (PDA) detector (Table A-1, System C). The cis-isomer was not detected with a limit of detection of 0.018% weight basis. Karl Fisher titration performed at Galbraith Laboratories (Knoxville, TN) indicated a water content of 0.24%. The overall purity of lot 156AB was determined to be >99%.

Accelerated stability studies were conducted using the HPLC/UV protocol outlined above (Table A-1, System A). Stability was confirmed when protected from light and stored for 2 weeks at refrigerated (5°C), room (25°C), elevated (60°C), and frozen (−20°C) temperatures. Short-term storage (up to 2 weeks) of RES at room temperature when protected from light was deemed acceptable. The bulk chemical was stored at −20°C and protected from light, per the manufacturer’s recommendations.

### A.1.2 Methylcellulose

Methylcellulose used to make the 0.5% aqueous vehicle for gavage formulations was obtained from Spectrum (Gardena, CA) in three lots (UR1026, WL0069, and XB1050). Lot UR1026 was used in the 2-week studies and lots WL0069 and XB1050 were used in the 3-month studies.

The identity of the methylcellulose was confirmed by the study laboratory using FT-IR spectroscopy. Periodic purity analyses were performed by Galbraith Laboratories, Inc (Knoxville, TN) during the 3-month studies to determine the methoxy group content. The August 27, 2008 sample of lot WL0069, used to prepare the first dose formulation, had methoxy group content (32.2%) outside of the acceptance criteria of 27.5%–31.5%. A replacement lot (XB1050) was procured for the remaining formulations and was within the acceptance criteria for methoxy group content (29.3%).

Deionized water was used to make the 0.5% aqueous methylcellulose vehicle for gavage formulations.

## A.2 Preparation and Analysis of Dose Formulations

Dose formulations of RES in 0.5% methylcellulose were prepared following the protocols outlined in Table A-2. Formulations of 15.6, 31.2, 62.5, 125, and 250 mg/mL were used in the 2-week study in Fischer 344 (F344/NTac) rats, the 3-month study in Wistar Han rats, and the 2-week and 3-month studies in B6C3F1/N mice (Table A-2). Formulation concentrations and homogeneity were evaluated using HPLC/UV (Table A-1, System A). The method of preparation was validated for concentration ranges of 15−500 mg/mL. The RES formulations were confirmed to be resuspended after overnight storage by using a Polytron blender. Homogeneity was confirmed in 15.6 mg/mL preparations of dose formulation.

Stability of 15.6 mg/mL and 500 mg/mL formulations was confirmed for 42 days when protected from light and stored at room (~25°C), refrigerated (5°C), and freezer (−20°C) temperatures. A dosing simulation study on the 15.6 mg/mL formulation found that it was stable when stored at room temperature in an open amber vessel for 3 hours.

Analyses of preadministration and postadministration dose formulations were conducted throughout the study by the study laboratory (Table A-3, Table A-4, Table A-5, Table A-6). Postadministration samples were collected from the bottles used to dose the animals. Two dose formulations (31.2 and 125 mg/mL) prepared for the 2-week studies were >10% above the target concentrations and were replaced by freshly prepared formulations that met criteria prior to administration. Postadministration samples of the 62.5 mg/mL dose formulation in the 2-week studies for mice and F344/NTac rats were 17.7% and 19.5% above the target concentration, respectively (Table A-3, Table A-4). All preadministration samples from the 3-month studies were within 10% of the target concentrations, except for a 125 mg/mL formulation prepared for the mouse study in September 2008 which was replaced by a freshly prepared formulation that met criteria prior to administration. Postadministration samples of the 125 and 250 mg/mL dose formulations prepared in September 2008 for the 3-month mice studies were 10.9% and 14.3% above the target concentrations, respectively. All other samples were within 10% of the target concentration (Table A-3, Table A-4, Table A-5, Table A-6).

Table A-1 Chromatography Systems Used in the Two-week and Three-month Gavage Studies of Trans-resveratrol

Chromatography | Detection System | Column | Mobile Phase
System A
High-performance Liquid Chromatography | Ultraviolet (300 nm) | Zorbax Rx-C8 (250 mm × 4.6 mm ID) | A: water:methanol, pH ~4 (95:5) B: methanol:water, pH ~4 (90:10) Gradient program: A:B 90:10 for 5 minutes; 90:10 to 10:90 in 25 minutes; 10:90 to 90:10 in 20 minutes; hold at 90:10 for 10 minutes 1.0 mL/minute flow rate
System B
High-performance Liquid Chromatography | Ultraviolet (300 nm) | Waters Nova-Pak Phenyl 60Å (150 mm × 3.9 mm ID) | A: water:methanol, pH ~4 (95:5) B: methanol:water, pH ~4 (90:10) Gradient program: A:B 90:10 for 5 minutes; 90:10 to 10:90 in 25 minutes; 10:90 to 90:10 in 20 minutes; hold at 90:10 for 20 minutes 1.0 mL/minute flow rate
System C
High-performance Liquid Chromatography | Photodiode array (220–500 nm, extracted at 305 nm) | Waters Atlantis T3 C18 (100 mm × 2.1 mm ID, 3 μm particle size) with Waters Atlantis HILIC C18 guard (10 mm × 2.1 mm ID, 3 μm particle size) | A: 5 mM ammonium acetate in DI water:2-propanol (98:2, v/v) B: methanol:2-propanol (98:2, v/v) Gradient program: A:B 100:0 to 40:60 in 15 minutes; 40:60 to 0:100 in 0.5 minutes; hold at 0:100 for 2 minutes; 0:100 to 100:0 in 0.5 minutes; hold at 100:0 for 2 minutes 0.3 mL/minute flow rate

ID = internal diameter; DI = deionized.

Table A-2 Preparation and Storage of Dose Formulations in the Two-week and Three-month Gavage Studies of Trans-resveratrol

Preparation
Formulations of trans-resveratrol (lot 156AB) in 0.5% methylcellulose were prepared by transferring an appropriate amount of trans-resveratrol (determined by weight) into a graduated centrifuge tube containing ~4 mL of 0.5% methylcellulose. The contents were mixed by vortex action and sonification, then stored in a refrigerator overnight. The following day, the tube was removed from the refrigerator and sonicated for 20 minutes. The formulations were brought to volume with 0.5% methylcellulose and liquified by mixing with a Polytron blender.
Chemical Lot Number
Lot 156AB (Bayville Chemical Supply Co. Inc.)
Maximum Storage Time
42 days
Storage Conditions
Clear glass bottled placed in amber bags stored at ~2°C−8°C (refrigerated)
Study Laboratory
RTI International (Research Triangle Park, NC)

Table A-3 Results of Analyses of Dose Formulations Administered to Male and Female F344/NTac Rats in the Two-week Gavage Study of Trans-resveratrol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
October 2, 2006 | October 5–11, 2006 | 0 | BLOQ | NA
| | 15.6 | 15.25 ± 0.03 | −2.3
| | 31.2^b^ | 37.00 ± 0.07 | 18.6
| | 62.5 | 68.58 ± 0.49 | 9.7
| | 125^b^ | 143.0 ± 1.0 | 14.4
| | 250 | 270.4 ± 1.2 | 8.2
October 12, 2006 | October 12–13, 2006 | 31.2 | 30.53 ± 0.37 | −2.1
| | 125 | 121.7 ± 2.1 | −2.6
Animal Room Samples
October 2, 2006 | November 1–3, 2006 | 0 | BLOQ | NA
| | 15.6 | 15.95 ± 0.18 | 2.2
| | 62.5 | 74.70 ± 0.39 | 19.5
| | 250 | 276.1 ± 1.4 | 10.5
October 12, 2006 | November 1–3, 2006 | 31.2 | 30.83 ± 0.17 | −1.2
| | 125 | 119.2 ± 0.7 | −4.6

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

^b^ The formulation was not used in the study and was replaced by the formulation prepared on October 12, 2006.

Table A-4 Results of Analyses of Dose Formulations Administered to Male and Female B6C3F1/N Mice in the Two-week Gavage Study of Trans-resveratrol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
October 2, 2006 | October 5–11, 2006 | 0 | BLOQ | NA
| | 15.6 | 15.25 ± 0.03 | −2.3
| | 31.2^b^ | 37.00 ± 0.07 | 18.6
| | 62.5 | 68.58 ± 0.49 | 9.7
| | 125^b^ | 143.0 ± 1.0 | 14.4
| | 250 | 270.4 ± 1.2 | 8.2
October 12, 2006 | October 12–13, 2006 | 31.2 | 30.53 ± 0.37 | −2.1
| | 125 | 121.7 ± 2.1 | −2.6
Animal Room Samples
October 2, 2006 | November 1–3, 2006 | 0 | BLOQ | NA
| | 15.6 | 15.71 ± 0.07 | 0.7
| | 62.5 | 73.58 ± 0.61 | 17.7
| | 250 | 272.2 ± 2.0 | 8.9
October 12, 2006 | November 1–3, 2006 | 31.2 | 30.61 ± 0.11 | −1.9
| | 125 | 119.5 ± 3.8 | −4.4

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

^b^ The formulation was not used in the study and was replaced by the formulation prepared on October 12, 2006.

Table A-5 Results of Analyses of Dose Formulations Administered to Male and Female Wistar Han Rats in the Three-month Gavage Study of Trans-resveratrol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
October 1, 2008 | October 3, 2008 | 0 | BLOQ | NA
| | 15.6 | 16.3 ± 0.1 | 4.5
| | 15.6 | 16.3 ± 0.1 | 4.5
| | 15.6 | 16.1 ± 0.1 | 3.0
| | 31.2 | 32.6 ± 0.1 | 4.4
| | 31.2 | 32.1 ± 0.2 | 2.8
| | 31.2 | 31.6 ± 0.3 | 1.4
| | 62.5 | 65.0 ± 0.8 | 4.0
| | 62.5 | 64.5 ± 0.2 | 3.2
| | 62.5 | 65.4 ± 0.8 | 4.7
| | 125 | 126 ± 1 | 1.1
| | 125 | 130 ± 1 | 4.3
| | 125 | 128 ± 1 | 2.7
| | 250 | 257 ± 3 | 2.9
| | 250 | 257 ± 2 | 2.8
| | 250 | 260 ± 1 | 4.0
October 22, 2008 | October 29, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.8 ± 0.1 | 1.5
| | 15.6 | 15.7 ± 0.1 | 0.8
| | 15.6 | 15.6 ± 0.1 | 0.2
| | 31.2 | 31.6 ± 0.3 | 1.4
| | 31.2 | 31.5 ± 0.1 | 1.0
| | 31.2 | 31.1 ± 0.1 | −0.4
| | 62.5 | 63.3 ± 0.5 | 1.3
| | 62.5 | 62.2 ± 0.2 | −0.5
| | 62.5 | 62.9 ± 0.2 | 0.7
| | 125 | 126 ± 0 | 0.8
| | 125 | 125 ± 0 | 0.0
| | 125 | 121 ± 2 | −3.2
| | 250 | 247 ± 5 | −1.3
| | 250 | 252 ± 1 | 0.7
| | 250 | 250 ± NA^b^ | −0.2
November 21, 2008 | November 24, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.8 ± 0.1 | 1.1
| | 15.6 | 15.8 ± 0.2 | 1.1
| | 15.6 | 15.5 ± 0.1 | −0.8
| | 31.2 | 31.5 ± 0.1 | 1.0
| | 31.2 | 31.1 ± 0.3 | −0.3
| | 31.2 | 30.9 ± 0.1 | −1.0
| | 62.5 | 62.6 ± 0.5 | 0.1
| | 62.5 | 63.1 ± 0.2 | 1.0
| | 62.5 | 62.8 ± 0.2 | 0.4
| | 125 | 124 ± 1 | −1.1
| | 125 | 124 ± 1 | −1.1
| | 125 | 126 ± 1 | 0.5
| | 250 | 248 ± 1 | −0.8
| | 250 | 247 ± 1 | −1.2
| | 250 | 247 ± 1 | −1.2
January 20, 2009 | January 21, 2009 | 0 | BLOQ | NA
| | 15.6 | 15.8 ± 0.2 | 1.5
| | 15.6 | 15.8 ± 0.1 | 1.1
| | 31.2 | 31.6 ± 0.2 | 1.3
| | 31.2 | 31.6 ± 0.2 | 1.3
| | 62.5 | 63.6 ± 0.2 | 1.8
| | 62.5 | 60.5 ± 0.2 | −3.2
| | 125 | 127 ± 0 | 1.6
| | 125 | 126 ± 1 | 0.5
| | 250 | 249 ± 1 | −0.3
| | 250 | 251 ± 1 | 0.5
Animal Room Samples
October 1, 2008 | November 10, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.2 ± 0.3 | −2.3
| | 31.2 | 30.5 ± 0.8 | −2.2
| | 62.5 | 63.2 ± 0.1 | 1.1
| | 125 | 126 ± 1 | 0.8
| | 250 | 248 ± 2 | −0.7
October 22, 2008 | December 4, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.8 ± 0.2 | 1.5
| | 31.2 | 31.8 ± 0.2 | 1.8
| | 62.5 | 62.6 ± 0.5 | 0.1
| | 125 | 124 ± 1 | −1.1
| | 250 | 244 ± 6 | −2.5
November 21, 2008 | January 5, 2009 | 0 | BLOQ | NA
| | 15.6 | 15.7 ± 0.0 | 0.6
| | 31.2 | 30.8 ± 0.4 | −1.3
| | 62.5 | 62.4 ± 0.2 | −0.2
| | 125 | 124 ± 1 | −0.5
| | 250 | 249 ± 1 | −0.4
January 20, 2009 | March 2, 2009 | 0 | BLOQ | NA
| | 15.6 | 15.9 ± 0.1 | 2.1
| | 31.2 | 31.8 ± 0.1 | 1.8
| | 62.5 | 61.6 ± 0.1 | −1.5
| | 125 | 127 ± 0 | 1.6
| | 250 | 254 ± 1 | 1.7

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

^b^ Average of duplicate analysis.

Table A-6 Results of Analyses of Dose Formulations Administered to Male and Female B6C3F1/N Mice in the Three-month Gavage Study of Trans-resveratrol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
September 10, 2008 | September 12, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.3 ± 0.1 | −1.9
| | 31.2 | 30.5 ± 1.2 | −2.1
| | 62.5 | 62.8 ± 0.4 | 0.5
| | 125 | 140 ± 1 | 11.7
| | 125^b^ | 128 ± 3 | 2.4
| | 250 | 266 ± 1 | 6.4
October 1, 2008 | October 3, 2008 | 0 | BLOQ | NA
| | 15.6 | 16.3 ± 0.1 | 4.5
| | 15.6 | 16.3 ± 0.1 | 4.5
| | 15.6 | 16.1 ± 0.1 | 3.0
| | 31.2 | 32.6 ± 0.1 | 4.4
| | 31.2 | 32.1 ± 0.2 | 2.8
| | 31.2 | 31.6 ± 0.3 | 1.4
| | 62.5 | 65.0 ± 0.8 | 4.0
| | 62.5 | 64.5 ± 0.2 | 3.2
| | 62.5 | 65.4 ± 0.8 | 4.7
| | 125 | 126 ± 1 | 1.1
| | 125 | 130 ± 1 | 4.3
| | 125 | 128 ± 1 | 2.7
| | 250 | 257 ± 3 | 2.9
| | 250 | 257 ± 2 | 2.8
| | 250 | 260 ± 1 | 4.0
October 22, 2008 | October 29, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.8 ± 0.1 | 1.5
| | 15.6 | 15.7 ± 0.1 | 0.8
| | 15.6 | 15.6 ± 0.1 | 0.2
| | 31.2 | 31.6 ± 0.3 | 1.4
| | 31.2 | 31.5 ± 0.1 | 1.0
| | 31.2 | 31.1 ± 0.1 | −0.4
| | 62.5 | 63.3 ± 0.5 | 1.3
| | 62.5 | 62.2 ± 0.2 | −0.5
| | 62.5 | 62.9 ± 0.2 | 0.7
| | 125 | 126 ± 0 | 0.8
| | 125 | 125 ± 0 | 0.0
| | 125 | 121 ± 2 | −3.2
| | 250 | 247 ± 5 | −1.3
| | 250 | 252 ± 1 | 0.7
| | 250 | 250 ± NA^c^ | −0.2
November 21, 2008 | November 24, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.8 ± 0.1 | 1.1
| | 15.6 | 15.8 ± 0.2 | 1.1
| | 15.6 | 15.5 ± 0.1 | −0.8
| | 31.2 | 31.5 ± 0.1 | 1.0
| | 31.2 | 31.1 ± 0.3 | −0.3
| | 31.2 | 30.9 ± 0.1 | −1.0
| | 62.5 | 62.6 ± 0.5 | 0.1
| | 62.5 | 63.1 ± 0.2 | 1.0
| | 62.5 | 62.8 ± 0.2 | 0.4
| | 125 | 124 ± 1 | −1.1
| | 125 | 124 ± 1 | −1.1
| | 125 | 126 ± 1 | 0.5
| | 250 | 248 ± 1 | −0.8
| | 250 | 247 ± 1 | −1.2
| | 250 | 247 ± 1 | −1.2
Animal Room Samples
September 10, 2008 | October 22, 2008 | 0 | BLOQ | NA
| | 15.6 | 16.1 ± 0.0 | 3.2
| | 31.2 | 32.2 ± 0.3 | 3.3
| | 62.5 | 67.0 ± 0.6 | 7.2
| | 125^b^ | 139 ± 1 | 10.9
| | 250 | 286 ± 3 | 14.3
October 22, 2008 | December 4, 2008 | 0 | BLOQ | NA
| | 15.6 | 15.8 ± 0.1 | 1.3
| | 31.2 | 31.8 ± 0.2 | 1.9
| | 62.5 | 64.6 ± 0.4 | 3.4
| | 125 | 125 ± 1 | 0
| | 250 | 245 ± 1 | −2.0
November 21, 2008 | January 5, 2009 | 0 | BLOQ | NA
| | 15.6 | 15.6 ± 0.1 | −0.2
| | 31.2 | 31.1 ± 0.1 | −0.4
| | 62.5 | 62.9 ± 0.2 | 0.6
| | 125 | 126 ± 1 | 1.1
| | 250 | 247 ± 2 | −1.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

^b^ Formulation prepared in a separate batch on September 15, 2008.

^c^ Average of duplicate analysis.

Figure A-1

Infrared Absorption Spectrum of Trans-resveratrol

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Reference Sample of Trans-resveratrol