# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-101

Report Series: NTP Toxicity Report Series

Report Series Number: 101

Official citation: National Toxicology Program (NTP). 2021. NTP technical report on the toxicity studies of trimethylsilyldiazomethane (CASRN 18107-18-1) administered by nose-only inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 101.