# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicity Studies of Trimethylsilyldiazomethane (CASRN 18107-18-1) Administered by Nose-only Inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice by letter in November 2020 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicity Studies of Trimethylsilyldiazomethane Administered by Nose-only Inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Shama Ahmad, Ph.D.
  Associate Professor, Department of Anesthesiology and Perioperative Medicine
  The University of Alabama at Birmingham
  Birmingham, Alabama, USA
- Charlotte M. Keenan, V.M.D., DACVP, FIATP
  Principal Consultant
  C.M. Keenan ToxPath Consulting
  Doylestown, Pennsylvania, USA