# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies. evaluated and interpreted results, and reported findings
  W.M. Gwinn, Ph.D., Study Scientist
  M.F. Cesta, D.V.M., Ph.D., Co-study Pathologist
  D. Dixon, D.V.M., Ph.D., Co-study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  G.K. Roberts, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  B.R. Sparrow, Ph.D., Principal Investigator
  R. Barnewall, D.V.M., Ph.D.
  K.M. Patton, D.V.M., Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
- Conducted chemical procurement and test lot selection
  B.L. Burback, Ph.D., Principal Investigator
  T.A. Cristy, B.A.
- Conducted prestart and study-related chemistry and inhalation exposure activities
  A. Gupta, M.S.
  B.K. Hayden
  J.S. Richey, M.S.
- Pathology Associates, Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review and coordinated NTP Pathology Working Group on 5-day rats and mice (April 8, 2019)
  Q.D. Plumlee, D.V.M.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  H. Gong, M.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.